# APPENDIX D INTERVENTION CHARACTERISTICS TABLE

KQ2 POPULATIONS WITH PARENTAL HISTORIES OF SERIOUS MENTAL ILLNESS

KQ3 POPULATIONS WITH PARENTAL HISTORIES OF MILITARY SERVICE