# APPENDIX B EXCLUDED STUDIES

Exclude reasons: 1=Ineligible population, 2=Ineligible intervention, 3=Ineligible comparator, 4=Ineligible outcome, 5=Ineligible study design, 6=Ineligible publication type, 7=Ineligible Other.

Citation | Exclude Reason
Alexander, 2018^1^ | 5
Allchin, 2020^2^ | 4
Altafim, 2021^3^ | 1
Anis, 2022^4^ | 1
Aylward, 2019^5^ | 1
Ballard, 2018^6^ | 1
Barnicot, 2022^7^ | 1
Beardslee, 1997^8^ | 2
Beardslee, 1996^9^ | 2
Bearslee, 2007^10^ | 2
Becker, 2008^11^ | 1
Boyd, 2017^12^ | 1
Butler, 2000^13^ | 2
Byrne, 2019^14^ | 1
Casselman, 2015^15^ | 2
Cicchetti, 1999^16^ | 2
Coates, 2017^17^ | 4
Cooper, 2017^18^ | 1
Cullum, 2022^19^ | 1
Day, 2020^20^ | 1
DeGarmo, 2004^21^ | 1
Dempsey, 2016^22^ | 1
DeVoe, 2017^23^ | 1
Fernandez, 2004^24^ | 1
Franz, 2011^25^ | 1
Gewirtz, 2018^26^ | 5
Giallo, 2021^27^ | 1
Graham-Bermann, 2015^28^ | 1
Green, 2014^29^ | 1
Grip, 2011^30^ | 1
Grogan-Kaylor, 2019^31^ | 1
Gross, 2018^32^ | 1
Haight, 2005^33^ | 1
Heckman, 2004^34^ | 2
Howell, 2015^35^ | 1
Hurlburt, 2013^36^ | 1
Isobel, 2016^37^ | 1
Jaite, 2019^38^ | 1
Katz, 2020^39^ | 1
Kemmis-Riggs, 2022^40^ | 1
Kotter, 2011^41^ | 1
Lieberman, 2005^42^ | 1
Lindsey, 2022^43^ | 6
Love, 2016^44^ | 1
Maher, 2011^45^ | 1
Maybery, 2019^46^ | 2
McKee, 2014^47^ | 4
Mevissen, 2020^48^ | 2
Muzik, 2015^49^ | 1
Nielsen, 2006^50^ | 2
Patterson, 2004^51^ | 1
Peled, 2010^52^ | 1
Phelan, 2006^53^ | 1
Phelan, 2013^54^ | 1
Pihkala, 2010^55^ | 1
Potharst, 2019^56^ | 1
Punamaki, 2013^57^ | 2
Renneberg, 2016^58^ | 5
Renner, 2020^59^ | 1
Resnick, 1985^60^ | 1
Rosenblum, 2018^61^ | 1
Rosenblum, 2017^62^ | 1
Ross, 2020^63^ | 4
Saltzman, 2016^64^ | 5
Scannapieco, 1993^65^ | 1
Shepherd-Banigan, 2020^66^ | 1
Silovsky, 2022^67^ | 1
Smeerdijk, 2015^68^ | 1
Solantaus, 2010^69^ | 2
Solantaus, 2009^70^ | 1
Steele, 2019^71^ | 1
Stemmler, 2013^72^ | 1
Suchman, 2016^73^ | 7
Sullivan, 2004^74^ | 1
Ueno, 2019^75^ | 1
Valdez, 2013^76^ | 5
van der Asdonk, 2021^77^ | 1
van der Ende, 2014^78^ | 2
Waters, 2020^79^ | 1
Wiegand-Grefe, 2016^80^ | 1
Wretman, 2019^81^ | 1

1 Alexander K. Integrative Review of the Relationship Between Mindfulness-Based Parenting Interventions and Depression Symptoms in Parents. JOGNN - Journal of Obstetric, Gynecologic, & Neonatal Nursing. 2018;47(2):184–190.
2 Allchin B, Weimand BM, O’Hanlon B, . Continued capacity: Factors of importance for organizations to support continued Let’s Talk practice - a mixed-methods study. International Journal of Mental Health Nursing. 2020;29(6):1131–1143.32597013
3 Altafim ERP, de Oliveira RC, Linhares MBM. Maternal history of childhood violence in the context of a parenting program. Journal of Child and Family Studies. 2021:No Pagination Specified.
4 Anis L, Ross K, Ntanda H, . Effect of Attachment and Child Health (ATTACH<sup>TM</sup>) Parenting Program on Parent-Infant Attachment, Parental Reflective Function, and Parental Depression. International Journal of Environmental Research & Public Health [Electronic Resource]. 2022;19(14):10.
5 Aylward P. An integrated group parenting model for mums with mental health issues and their babies: Findings from a participatory action research evaluation of the South Australian ACORN Program. International Journal of Integrated Care (IJIC). 2019;19(S1):1–2.
6 Ballard J, Wieling E, Forgatch M. Feasibility of Implementation of a Parenting Intervention with Karen Refugees Resettled from Burma. Journal of Marital & Family Therapy. 2018;44(2):220–234.29194666
7 Barnicot K, Welsh M, Kalwarowsky S, . Video feedback parent-infant intervention for mothers experiencing enduring difficulties in managing emotions and relationships: A randomised controlled feasibility trial. British Journal of Clinical Psychology. 2022;26:26.
8 Beardslee WR, Salt P, Versage EM, . Sustained change in parents receiving preventive interventions for families with depression. American Journal of Psychiatry. 1997;154(4):510–5.9090338
9 Beardslee WR, Wright E, Rothberg PC, . Response of families to two preventive intervention strategies: Long-term differences in behavior and attitude change. Journal of the American Academy of Child and Adolescent Psychiatry. 1996;35(6):774–782.8682758
10 Beardslee WR, Wright EJ, Gladstone TR, . Long-term effects from a randomized trial of two public health preventive interventions for parental depression. Journal of Family Psychology. 2007;21(4):703–13.18179342
11 Becker KD, Mathis G, Mueller CW, . Community-based treatment outcomes for parents and children exposed to domestic violence. Journal of Emotional Abuse. 2008;8(1–2):187–204.
12 Boyd RC, Gerdes M, Rothman B, . A Toddler Parenting Intervention in Primary Care for Caregivers With Depression Symptoms. Journal of Primary Prevention. 2017;38(5):465–480.28733799
13 Butler SF, Budman SH, Beardslee W. Risk reduction in children from families with parental depression: A videotape psychoeducation program. National Academies of Practice Forum: Issues in Interdisciplinary Care. 2000;2(4):267–276.
14 Byrne G, Sleed M, Midgley N, . Lighthouse Parenting Programme: Description and pilot evaluation of mentalization-based treatment to address child maltreatment. Clinical Child Psychology & Psychiatry. 2019;24(4):680–693.30387373
15 Casselman RB, Pemberton JR. ACT-based parenting group for veterans with PTSD: Development and preliminary outcomes. American Journal of Family Therapy. 2015;43(1):57–66.
16 Cicchetti D, Toth SL, Rogosch FA. The efficacy of toddler-parent psychotherapy to increase attachment security in offspring of depressed mothers. Attachment & Human Development. 1999;1(1):34–66.11707882
17 Coates D, Phelan R, Heap J, . “Being in a group with others who have mental illness makes all the difference”: The views and experiences of parents who attended a mental health parenting program. Children & Youth Services Review. 2017;78:104–111.
18 Cooper V, Reupert A. “Let’s Talk About Children” resource: A parallel mixed method evaluation. Social Work in Mental Health. 2017;15(1):47–65.
19 Cullum KA, Goodman SH, Garber J, . A positive parenting program to enhance positive affect in children of previously depressed mothers. Journal of Family Psychology. 2022;36(5):692–703.35266774
20 Day C, Briskman J, Crawford MJ, . An intervention for parents with severe personality difficulties whose children have mental health problems: a feasibility RCT. Health Technology Assessment (Winchester, England). 2020;24(14):1–188.
21 DeGarmo DS, Patterson GR, Forgatch MS. How do outcomes in a specified parent training intervention maintain or wane over time? Prevention Science. 2004;5(2):73–89.15134313
22 Dempsey J, McQuillin S, Butler AM, . Maternal Depression and Parent Management Training Outcomes. Journal of Clinical Psychology in Medical Settings. 2016;23(3):240–6.27448152
23 DeVoe ER, Paris R, Emmert-Aronson B, . A randomized clinical trial of a postdeployment parenting intervention for service members and their families with very young children. Psychological Trauma:Theory, Pesearch, Practice and Policy. 2017;9(Suppl 1):25–34.
24 Fernandez E. Effective interventions to promote child and family wellness: a study of outcomes of intervention through Children’s Family Centres. Child & Family Social Work. 2004;9(1):91–104.
25 Franz M, Weihrauch L, Schäfer R. PALME: A preventive parental training program for single mothers with preschool aged children. Journal of Public Health. 2011;19(4):305–319.
26 Gewirtz AH. A Call for Theoretically Informed and Empirically Validated Military Family Interventions. Journal of Family Theory & Review. 2018;10(3):587–601.30416241
27 Giallo R, Rominov H, Fisher C, . A mixed-methods feasibility study of the Home Parenting Education and Support Program for families at risk of child maltreatment and recurrence in Australia. Child Abuse & Neglect. 2021;122:105356.34634523
28 Graham-Bermann SA, Miller-Graff L. Community-based intervention for women exposed to intimate partner violence: A randomized control trial. Journal of Family Psychology. 2015;29(4):537–47.26030027
29 Green BL, Tarte JM, Harrison PM, . Results from a randomized trial of the Healthy Families Oregon accredited statewide program: Early program impacts on parenting. Children & Youth Services Review. 2014;44:288–298.
30 Grip K, Almqvist K, Broberg AG. Effects of a group-based intervention on psychological health and perceived parenting capacity among mothers exposed to intimate partner violence (ipv): a preliminary study. Smith College Studies in Social Work (Taylor & Francis Ltd). 2011;81(1):81–100.
31 Grogan-Kaylor A, Galano MM, Howell KH, . Reductions in Parental Use of Corporal Punishment on Pre-School Children Following Participation in the Moms’ Empowerment Program. Journal of Interpersonal Violence. 2019;34(8):1563–1582.27283137
32 Gross D, Belcher HME, Budhathoki C, . Does Parent Training Format Affect Treatment Engagement? A Randomized Study of Families at Social Risk? Journal of Child & Family Studies. 2018;27(5):1579–1593.29713137
33 Haight WL, Mangelsdorf S, Black J, . Enhancing parent-child interaction during foster care visits: experimental assessment of an intervention. Child Welfare. 2005;84(4):459–81.16117259
34 Heckman JP, Hutchins FA, Thom JC, . Allies: Integrating Women’s Alcohol, Drug, Mental Health and Trauma Treatment in a County System. Alcoholism Treatment Quarterly. 2004;22(3–4):161–180.
35 Howell KH, Miller LE, Lilly MM, . Strengthening positive parenting through intervention: evaluating the Moms’ Empowerment Program for women experiencing intimate partner violence. Journal of Interpersonal Violence. 2015;30(2):232–52.24832954
36 Hurlburt MS, Nguyen K, Reid J, . Efficacy of the Incredible Years group parent program with families in Head Start who self-reported a history of child maltreatment. Child Abuse & Neglect. 2013;37(8):531–43.23306144
37 Isobel S, Meehan F, Pretty D. An Emotional Awareness Based Parenting Group for Parents with Mental Illness: A Mixed Methods Feasibility Study of Community Mental Health Nurse Facilitation. Archives of Psychiatric Nursing. 2016;30(1):35–40.26804499
38 Jaite C, van Noort BM, Vloet TD, . A multicentre randomized controlled trial on trans-generational attention deficit/hyperactivity disorder (ADHD) in mothers and children (AIMAC): an exploratory analysis of predictors and moderators of treatment outcome. Zeitschrift fur Kinder-und Jugendpsychiatrie und Psychotherapie. 2019;47(1):49–65.30084719
39 Katz LF, Gurtovenko K, Maliken A, . An emotion coaching parenting intervention for families exposed to intimate partner violence. Developmental Psychology. 2020;56(3):638–651.32077730
40 Kemmis-Riggs J, Dickes A, Rogers K, . Improving Parent-Child Relationships for Young Parents in the Shadow of Complex Trauma: A Single-Case Experimental Design Series. Child Psychiatry & Human Development. 2022;27:27.
41 Kotter C, Stemmler M, Losel F, . Medium-term effects of the EFFEKT-E preventive program for emotionally distressed mothers and their children in relation to psychosocial risk. Zeitschrift fur Gesundheitspsychologie. 2011;19(3):122–133.
42 Lieberman AF, Van Horn P, Ippen CG. Toward evidence-based treatment: child-parent psychotherapy with preschoolers exposed to marital violence. J Am Acad Child Adolesc Psychiatry. 2005;44(12):1241–8.16292115
43 Lindsey M, Sullivan K, Chemtob C, . A randomized controlled trial to assess the efficacy of Parenting-STAIR in treating maternal PTSD to reduce maltreatment recidivism: protocol for the Safe Mothers, Safe Children study. Trials [Electronic Resource]. 2022;23(1):432.35606818
44 Love SM, Sanders MR, Turner KM, . Social media and gamification: Engaging vulnerable parents in an online evidence-based parenting program. Child Abuse & Neglect. 2016;53:95–107.26880281
45 Maher EJ, Marcynszyn LA, Corwin TW, . Dosage matters: the relationship between participation in the nurturing parenting program for infants, toddlers, and preschoolers and subsequent child maltreatment. Children & Youth Services Review. 2011;33(8):1426–1434.
46 Maybery D, Goodyear M, Reupert A, . A mixed method evaluation of an intervention for parents with mental illness. Clinical Child Psychology & Psychiatry. 2019;24(4):717–727.30696254
47 McKee LG, Parent J, Forehand R, . Reducing youth internalizing symptoms: effects of a family-based preventive intervention on parental guilt induction and youth cognitive style. Development & Psychopathology. 2014;26(2):319–32.24438999
48 Mevissen L, Ooms-Evers M, Serra M, . Feasibility and potential effectiveness of an intensive trauma-focused treatment programme for families with PTSD and mild intellectual disability. European Journal of Psychotraumatology. 2020;11(1):1777809.33029319
49 Muzik M, Rosenblum KL, Alfafara EA, . Mom Power: preliminary outcomes of a group intervention to improve mental health and parenting among high-risk mothers. Archives of Women’s Mental Health. 2015;18(3):507–21.
50 Nielsen N. Evaluation of family therapy. Nordic Journal of Psychiatry. 2006;60(2):137–143.16635933
51 Patterson GR, DeGarmo D, Forgatch MS. Systematic changes in families following prevention trials. Journal of Abnormal Child Psychology. 2004;32(6):621–33.15648529
52 Peled E, Davidson-Arad B, Perel G. The mothering of women abused by their partner: An outcome evaluation of a group intervention. Research on Social Work Practice. 2010;20(4):391–402.
53 Phelan R, Lee L, Howe D, . Parenting and mental illness: a pilot group programme for parents. Australasian Psychiatry. 2006;14(4):399–402.17116080
54 Phelan RF, Howe DJ, Cashman EL, . Enhancing parenting skills for parents with mental illness: the Mental Health Positive Parenting Program. Medical Journal of Australia. 2013;199(3 Suppl):S30–3.25369846
55 Pihkala H, Cederstrom A, Sandlund M. Beardslee’s preventive family intervention for children of mentally ill parents: A Swedish National Survey. International Journal of Mental Health Promotion. 2010;12(1):29–38.
56 Potharst ES, Boekhorst M, Cuijlits I, . A Randomized Control Trial Evaluating an Online Mindful Parenting Training for Mothers With Elevated Parental Stress. Frontiers in Psychology. 2019;10:1550.31379646
57 Punamaki RL, Paavonen J, Toikka S, . Effectiveness of preventive family intervention in improving cognitive attributions among children of depressed parents: a randomized study. Journal of Family Psychology. 2013;27(4):683–90.23978323
58 Renneberg B, Rosenbach C. “There is not much help for mothers like me”: Parenting Skills for Mothers with Borderline Personality Disorder - a newly developed group training program. Borderline Personality Disorder and Emotion Dysregulation. 2016;3:16.27980787
59 Renner LM, Driessen MC, Lewis-Dmello A. A Pilot Study Evaluation of a Parent Group for Survivors of Intimate Partner Violence. Journal of Family Violence. 2020;35(2):203–215.
60 Resnick G. Enhancing parental competencies for high risk mothers: an evaluation of prevention effects. Child Abuse & Neglect. 1985;9(4):479–89.4084827
61 Rosenblum K, Lawler J, Alfafara E, . Improving Maternal Representations in High-Risk Mothers: A Randomized, Controlled Trial of the Mom Power Parenting Intervention. Child Psychiatry & Human Development. 2018;49(3):372–384.28936602
62 Rosenblum KL, Muzik M, Morelen DM, . A community-based randomized controlled trial of Mom Power parenting intervention for mothers with interpersonal trauma histories and their young children. Archives of Women’s Mental Health. 2017;20(5):673–686.
63 Ross AM, DeVoe ER, Steketee G, . Outcomes of a reflective parenting program among military spouses: The moderating role of social support. Journal of Family Psychology. 2020;34(4):402–413.32027150
64 Saltzman WR, Lester P, Milburn N, . Pathways of Risk and Resilience: Impact of a Family Resilience Program on Active-Duty Military Parents. Family Process. 2016;55(4):633–646.27597440
65 Scannapieco M. The importance of family functioning to prevention of placement: A study of family preservation services. Child & Adolescent Social Work Journal. 1993;10(6):509–520.
66 Shepherd-Banigan M, Jones KA, Wang K, . Mechanisms Through Which a Family Caregiver Coaching Intervention Might Reduce Anxiety Among Children in Military Households. Maternal & Child Health Journal. 2020;24(10):1248–1258.32749616
67 Silovsky J, Bard D, Owora AH, . Risk and Protective Factors Associated with Adverse Childhood Experiences in Vulnerable Families: Results of a Randomized Clinical Trial of SafeCare R. Child Maltreatment. 2022:10775595221100723.
68 Smeerdijk M, Keet R, van Raaij B, . Motivational interviewing and interaction skills training for parents of young adults with recent-onset schizophrenia and co-occurring cannabis use: 15-month follow-up. Psychological Medicine. 2015;45(13):2839–48.25959502
69 Solantaus T, Paavonen EJ, Toikka S, . Preventive interventions in families with parental depression: children’s psychosocial symptoms and prosocial behaviour. European Child & Adolescent Psychiatry. 2010;19(12):883–92.20890622
70 Solantaus T, Toikka S, Alasuutari M, . Safety, feasibility and family experiences of preventive interventions for children and families with parental depression. International Journal of Mental Health Promotion. 2009;11(4):15–24.
71 Steele H, Murphy A, Bonuck K, . Randomized control trial report on the effectiveness of Group Attachment-Based Intervention (GABI©): Improvements in the parent-child relationship not seen in the control group. Development & Psychopathology. 2019;31(1):203–217.30757992
72 Stemmler M, Kötter C, Bühler A, . Prevention of familial transmission of depression through a family-oriented programme targeting parenting as well as the child’s social competence. Journal of Children’s Services. 2013;8(1):5–20.
73 Suchman NE, Ordway MR, de Las Heras L, . Mothering from the Inside Out: results of a pilot study testing a mentalization-based therapy for mothers enrolled in mental health services. Attachment & Human Development. 2016;18(6):596–617.27575343
74 Sullivan M, Egan M, Gooch M. Conjoint Interventions for Adult Victims and Children of Domestic Violence: A Program Evaluation. Research on Social Work Practice. 2004;14(3):163–170.
75 Ueno R, Osada H, Solantaus T, . Safety, Feasibility, Fidelity, and Perceived Benefits of an Intervention for Parents with Mood Disorders and Their Children — “Let’s Talk About Children” in Japan. Journal of Family Psychotherapy. 2019;30(4):272–291.
76 Valdez CR, Padilla B, Moore SM, . Feasibility, acceptability, and preliminary outcomes of the Fortalezas Familiares intervention for latino families facing maternal depression. Family Process. 2013;52(3):394–410.24033238
77 van der Asdonk S, Cyr C, Alink L. Improving parent-child interactions in maltreating families with the Attachment Video-feedback Intervention: Parental childhood trauma as a moderator of treatment effects. Attachment & Human Development. 2021;23(6):876–896.32746730
78 van der Ende PC, van Busschbach JT, Nicholson J, . Parenting and psychiatric rehabilitation: can parents with severe mental illness benefit from a new approach? Psychiatric Rehabilitation Journal. 2014;37(3):201–8.24866839
79 Waters SF, Hulette A, Davis M, . Evidence for attachment vitamins: A trauma-informed universal prevention programme for parents of young children. Early Child Development and Care. 2020;190(7):1109–1114.
80 Wiegand-Grefe S, Alberts J, Petermann F, . Differential perspectives on family functioning and interfamilial relationships: The effect of a manualized intervention program on children of mentally ill parents. Kindheit und Entwicklung: Zeitschrift fur Klinische Kinderpsychologie. 2016;25(2):77–88.
81 Wretman CJ, Rizo CF, Macy RJ, . A novel intervention for system-involved intimate partner violence survivors: Changes in parenting. Research on Social Work Practice. 2019;29(3):268–280.