# APPENDIX A SEARCH STRATEGIES

Database: MEDLINE (via Ovid)

Search date: 9/7/2022

Note: Ovid MEDLINE(R) ALL 1946 to September 06, 2022

Search Set | Search Strategy | Results
#1; Parenting skills training terms | *parents/ed or ((parent or parents or parental or parenting) adj6 (training or trainings or skill or skills or education or educational or intervention or interventions or interventional or program or programs or programme or programmes or programming or course or courses or workshop or workshops)).ti,ab. or (triple P or “positive parenting program” or “positive parenting programs”).ti,ab. | 39,061
#2; Psychological trauma terms | exp “Trauma and Stressor Related Disorders”/ or exp “Stress Disorders, Traumatic”/ or exp Combat Disorders/ or exp Psychological Trauma/ or exp Sexual Trauma/ or exp “Stress Disorders, Post-Traumatic”/ or exp “Stress Disorders, Traumatic, Acute”/ or exp Domestic Violence/ or exp Spouse Abuse/ or exp Stalking/ or exp Rape/ or (trauma or traumas or traumatic or psychotrauma or psychotraumatic or PTSD or posttraumatic or post-traumatic or “combat disorder” or “combat disorders” or stalking or stalker or stalkers or rape or rapes or raped).ti,ab. or ((sex or sexual or sexually or domestic or “intimate partner” or “intimate partners” or spouse or spouses or spousal or physical or physically) adj2 (abuse or abuses or abused or abuser or abusers or violence or assault or assaults or assaulted)).ti,ab. or ((psychological or psychologically or psychologic) adj2 (aggression or aggressor or aggressors or injury or injuries or abuse or abuses or abusive)).ti,ab. | 507,155
#3; Military / veterans terms | exp veterans/ or exp veterans health/ or exp hospitals, veterans/ or exp veterans health services/ or exp military personnel/ or exp military family/ or exp “psychology, military”/ or exp military psychiatry/ or exp “military health services”/ or exp military health/ or (veteran or veterans or military or army or navy or naval or marine or marines or “service member” or “service members” or “service men” or servicemen or “service women” or servicewomen or postdeployment or post-deployment or “post deployment” or “after deployment”).ti,ab | 235,049
#4; Mental illness terms | exp “Bipolar and Related Disorders”/ or exp Bipolar Disorder/ or Depressive Disorder/ or exp Depressive Disorder, Major/ or exp Depressive Disorder, Treatment-Resistant/ or *Mood Disorders/ or *Mental Disorders/ or Personality Disorders/ or exp Antisocial Personality Disorder/ or exp Borderline Personality Disorder/ or exp Compulsive Personality Disorder/ or exp Histrionic Personality Disorder/ or exp Paranoid Personality Disorder/ or exp Schizoid Personality Disorder/ or exp Schizotypal Personality Disorder/ or exp Schizophrenia Spectrum and Other Psychotic Disorders/ or exp Affective Disorders, Psychotic/ or exp Paranoid Disorders/ or exp Psychotic Disorders/ or exp Schizophrenia/ or (“mental illness” or “mental illnesses” or “mentally ill” or “psychiatric illness” or “psychiatric illnesses” or “psychiatric disorder” or “psychiatric disorders” or “mental disorder” or “mental disorders” or “mood disorder” or “mood disorders” or depression or depressive or bipolar or schizophrenia or schizophrenic OR schizophreniform OR schizoaffective or schizo-affective or “schizo affective” or schizoid OR schizoidism OR schizotypal or schizo-typal or “schizo typal” or psychotic or psychosis or psychoses or mania or manic OR psychopath OR psychopaths OR psychopathy OR psychopathic OR paranoia or paranoid or “personality disorder” or “personality disorders”).ti,ab. or ((antisocial or borderline or compulsive or obsessive or histrionic) adj2 (disorder or disorders)).ti,ab. | 790,619
#5; Combining | 2 or 3 or 4 | 1,461,170
#6; Combining | 1 and 5 | 5,486
#7; Study Design: EPOC filter or RCTs | exp “Cohort Studies”/ or exp “Longitudinal Studies”/ or exp “Follow-Up Studies”/ or exp “Evaluation Studies as Topic”/ or exp “Controlled Before-After Studies”/ or exp “Interrupted Time Series Analysis”/ or “Randomized Controlled Trial".pt. or “Controlled Clinical Trial".pt. or “Clinical Trial".pt. or “Evaluation Studies".pt. or “Comparative Study".pt. or (randomized or randomised or randomization or randomisation or placebo or randomly or trial or trials or groups or “evaluation study” or “evaluation studies” or “intervention study” or “intervention studies” or cohort or cohorts or longitudinal or longitudinally or prospective or prospectively or “follow up” or follow-up or followup or “comparative study” or “comparative studies” or nonrandom or “non-random” or nonrandomized or “non-randomized” or nonrandomised or “non-randomised” or quasi-experiment* or quaziexperiment* or quasiexperiment* or quaziexperiment* or quasirandom* or quazirandom* or quasi-random* or quazi-random* or quasi-control* or quazi-control* or quasicontrol* or quazicontrol*).ti,ab. or (controlled AND study).ti,ab. or (“pre-post” or “pre post” or “posttest” or “post-test” or “post test” or pretest or “pre-test” or “pre test” or “repeated measure” or “repeated measures”).ti,ab. or (before AND after).ti,ab. or (before AND during).ti,ab. or (“time series” AND interrupt*).ti,ab. or (“time points” AND (multiple or one or two or three or four or five or six or seven or eight or nine or ten or month or monthly or day or daily or week or weekly or hour or hourly)).ti,ab. | 9,172,480
#8; combining | 6 and 7 | 3,299
#9; Exclusions – study designs | 8 not (case reports or editorial or letter or comment or congress).pt. | 3,264
#10; Exclusions – animal-only | 9 not (exp animals/ not exp humans/) | 3,263

Database: Embase (via Elsevier)

Search date: 9/7/2022

Note: Search from Results

Search Set | Search Strategy | Results
#1; Parenting skills training terms | ((parent OR parents OR parental OR parenting) NEAR/6 (training OR trainings OR skill OR skills OR education OR educational OR intervention OR interventions OR interventional OR program OR programs OR programme OR programmes OR programming OR course OR courses OR workshop OR workshops)):ti,ab OR (triple P OR ‘positive parenting program’ OR ‘positive parenting programs’):ti,ab | 82,705
#2; Psychological trauma terms | ‘posttraumatic stress disorder’/exp OR ‘combat stress’/exp OR ‘sexual trauma’/exp OR ‘psychotrauma’/exp OR ‘acute stress disorder’/exp OR ‘domestic violence’/exp OR ‘partner violence’/exp OR ‘stalking’/exp OR ‘rape’/exp OR (trauma OR traumas OR traumatic OR psychotrauma OR psychotraumatic OR PTSD OR posttraumatic OR ‘combat disorder’ OR ‘combat disorders’ OR stalking OR stalker OR stalkers OR rape OR rapes OR raped):ti,ab OR ((sex OR sexual OR sexually OR domestic OR ‘intimate partner’ OR ‘intimate partners’ OR spouse OR spouses OR spousal OR physical OR physically) NEAR/2 (abuse OR abuses OR abused OR abuser OR abusers OR violence OR assault OR assaults OR assaulted)):ti,ab OR ((psychological OR psychologically OR psychologic) NEAR/2 (aggression OR aggressor OR aggressors OR injury OR injuries OR abuse OR abuses OR abusive)):ti,ab | 697,740
#3; Military / veterans terms | ‘veteran’/exp OR ‘veterans health’/exp OR ‘military health’/exp OR ‘military health service’/exp OR ‘veterans health service’/exp OR ‘military personnel’/exp OR ‘military medical personnel’/exp OR ‘military family’/exp OR ‘military spouse’/exp OR ‘military medicine’/exp OR ‘military hospital’/exp OR (veteran OR veterans OR military OR army OR navy OR naval OR marine OR marines OR ‘service member’ OR ‘service members’ OR ‘service men’ OR servicemen OR ‘service women’ OR servicewomen OR postdeployment OR ‘post deployment’ OR ‘after deployment’):ti,ab | 292,425
#4; Mental illness terms | ‘bipolar disorder’/exp OR ‘depression’/exp OR ‘mood disorder’/exp OR ‘mental disease’/mj OR ‘personality disorder’/exp OR ‘antisocial personality disorder’/exp OR ‘borderline state’/exp OR ‘compulsive personality disorder’/exp OR ‘histrionic personality disorder’/exp OR ‘paranoid personality disorder’/exp OR ‘psychopathy’/exp OR ‘schizoidism’/exp OR ‘schizotypal personality disorder’/exp OR ‘schizophrenia spectrum disorder’/exp OR ‘brief psychotic disorder’/exp OR ‘schizoaffective psychosis’/exp OR ‘schizophrenia’/exp OR ‘schizophreniform disorder’/exp OR (‘mental illness’ OR ‘mental illnesses’ OR ‘mentally ill’ OR ‘psychiatric illness’ OR ‘psychiatric illnesses’ OR ‘psychiatric disorder’ OR ‘psychiatric disorders’ OR ‘mental disorder’ OR ‘mental disorders’ OR ‘mood disorder’ OR ‘mood disorders’ OR depression OR depressive OR bipolar OR schizophrenia OR schizophrenic OR schizophreniform OR schizoaffective OR ‘schizo affective’ OR schizoid OR schizoidism OR schizotypal OR ‘schizo typal’ OR psychotic OR psychosis OR psychoses OR mania OR manic OR psychopath OR psychopaths OR psychopathy OR psychopathic OR paranoia OR paranoid OR ‘personality disorder’ OR ‘personality disorders’):ti,ab OR ((antisocial OR borderline OR compulsive OR obsessive OR histrionic) NEAR/2 (disorder OR disorders)):ti,ab | 1,343,265
#5; Combining | #2 OR #3 OR #4 | 2,216,628
#6; Combining | #1 AND #5 | 8,681
#7; Study Design: EPOC filter OR RCTs | ‘cohort analysis’/exp OR ‘longitudinal study’/de OR ‘randomized controlled trial’/exp OR ‘controlled clinical trial’/exp OR ‘single blind procedure’/exp OR ‘double blind procedure’/exp OR ‘crossover procedure’/exp OR ‘crossover procedure’:de OR ‘double-blind procedure’:de OR ‘randomized controlled trial’:de OR ‘single-blind procedure’:de OR (random* OR factorial* OR crossover* OR cross NEXT/1 over* OR placebo* OR doubl* NEAR/1 blind* OR singl* NEAR/1 blind* OR assign* OR allocat* OR volunteer*):ti,ab OR (‘evaluation study’ OR ‘evaluation studies’ OR ‘intervention study’ OR ‘intervention studies’ OR cohort OR cohorts OR longitudinal OR longitudinally OR prospective OR prospectively OR ‘follow up’ OR follow-up OR followup OR ‘comparative study’ OR ‘comparative studies’ OR nonrandom OR ‘non-random’ OR nonrandomized OR ‘non-randomized’ OR nonrandomised OR ‘non-randomised’ OR quasi-experiment* OR quazi-experiment* OR quasiexperiment* OR quaziexperiment* OR quasirandom* OR quazirandom* OR quasi-random* OR quazi-random* OR quasi-control* OR quazi-control* OR quasicontrol* OR quazicontrol*):ti,ab OR (controlled AND study):ti,ab OR (‘pre-post’ OR ‘pre post’ OR ‘posttest’ OR ‘post-test’ OR ‘post test’ OR pretest OR ‘pre-test’ OR ‘pre test’ OR ‘repeated measure’ OR ‘repeated measures’):ti,ab OR (before AND after):ti,ab OR (before AND during):ti,ab OR (‘time series’ AND interrupt*):ti,ab OR (‘time points’ AND (multiple OR one OR two OR three OR four OR five OR six OR seven OR eight OR nine OR ten OR month OR monthly OR day OR daily OR week OR weekly OR hour OR hourly)):ti,ab | 7,725,543
#8; combining | #6 AND #7 | 4,250
#9; Exclusions – study designs | #8 NOT (‘case report’/exp OR ‘case study’/exp OR ‘editorial’/exp OR [editorial]/lim OR ‘letter’/exp OR [letter]/lim OR ‘note’/exp OR [note]/lim OR [conference abstract]/lim OR ‘conference abstract’/exp OR ‘conference abstract’/it) | 3,206
#10; Exclusions – animal-only | #9 AND [humans]/lim | 3,149

Database: APA PsycINFO (via Ovid)

Search date: 9/7/2022

Note: APA PsycInfo 1806 to August Week 5 2022

Search Set | Search Strategy | Results
#1; Parenting skills training terms | ((parent or parents or parental or parenting) adj6 (training or trainings or skill or skills or education or educational or intervention or interventions or interventional or program or programs or programme or programmes or programming or course or courses or workshop or workshops)).ti,ab. or (triple P or “positive parenting program" or “positive parenting programs”).ti,ab. | 48,106
#2; Psychological trauma terms | “stress and trauma related disorders”/ or acute stress disorder/ or exp posttraumatic stress disorder/ or posttraumatic stress/ OR trauma/ or emotional trauma/ or traumatic experiences/ or combat experience/ or exp intimate partner violence/ or domestic violence/ or emotional abuse/ or physical abuse/ or exp sexual abuse/ or stalking/ or rape/ or (trauma or traumas or traumatic or psychotrauma or psychotraumatic or PTSD or posttraumatic or post-traumatic or “combat disorder” or “combat disorders” or stalking or stalker or stalkers or rape or rapes or raped).ti,ab. or ((sex or sexual or sexually or domestic or “intimate partner” or “intimate partners” or spouse or spouses or spousal or physical or physically) adj2 (abuse or abuses or abused or abuser or abusers or violence or assault or assaults or assaulted)).ti,ab. or ((psychological or psychologically or psychologic) adj2 (aggression or aggressor or aggressors or injury or injuries or abuse or abuses or abusive)).ti,ab. | 211,281
#3; Military / veterans terms | exp military personnel/ or military veterans/ or military families/ or exp Military Enlistment/ or exp Military Psychology/ or exp Military Medical Personnel/ or exp Military Psychiatry/ or exp Military Deployment/ or (veteran or veterans or military or army or navy or naval or marine or marines or “service member” or “service members” or “service men” or servicemen or “service women” or servicewomen or postdeployment or post-deployment or “post deployment” or “after deployment”).ti,ab | 61,924
#4; Mental illness terms | exp bipolar disorder/ or bipolar i disorder/ or bipolar ii disorder/ or exp mania/ or exp borderline states/ or exp chronic mental illness/ or exp dissociative disorders/ or *mental disorders/ or exp personality disorders/ or antisocial personality disorder/ or avoidant personality disorder/ or borderline personality disorder/ or histrionic personality disorder/ or obsessive compulsive personality disorder/ or paranoid personality disorder/ or schizoid personality disorder/ or schizotypal personality disorder/ or serious mental illness/ or affective disorders/ or exp major depression/ or psychosis/ or acute psychosis/ or affective psychosis/ or chronic psychosis/ or “paranoia (psychosis)”/ or exp schizophrenia/ or schizophreniform disorder/ or schizoid personality disorder/ or schizotypal personality disorder/ or (“mental illness” or “mental illnesses” or “mentally ill” or “psychiatric illness” or “psychiatric illnesses” or “psychiatric disorder” or “psychiatric disorders” or “mental disorder” or “mental disorders” or “mood disorder” or “mood disorders” or depression or depressive or bipolar or schizophrenia or schizophrenic OR schizophreniform OR schizoaffective or schizo-affective or “schizo affective” or schizoid OR schizoidism OR schizotypal or schizo-typal or “schizo typal” or psychotic or psychosis or psychoses or mania or manic OR psychopath OR psychopaths OR psychopathy OR psychopathic OR paranoia or paranoid or “personality disorder” or “personality disorders”).ti,ab. or ((antisocial or borderline or compulsive or obsessive or histrionic) adj2 (disorder or disorders)).ti,ab. | 657,718
#5; Combining | 2 or 3 or 4 | 860,166
#6; Combining | 1 and 5 | 6,587
#7; Study Design: EPOC filter or RCTs | clinical trials/ or cohort analysis/ or followup studies/ or longitudinal studies/ or exp randomized controlled trials/ or exp randomized clinical trials/ or repeated measures/ or time series/ or (0300 or 0430 or 0450 or 0451).md. or (randomized or randomised or randomization or randomisation or placebo or randomly or trial or trials or groups or “evaluation study” or “evaluation studies” or “intervention study” or “intervention studies” or cohort or cohorts or longitudinal or longitudinally or prospective or prospectively or “follow up” or follow-up or followup or “comparative study” or “comparative studies” or nonrandom or “non-random” or nonrandomized or “non-randomized” or nonrandomised or “non-randomised” or quasi-experiment* or quazi-experiment* or quasiexperiment* or quaziexperiment* or quasirandom* or quazirandom* or quasi-random* or quazi-random* or quasi-control* or quazi-control* or quasicontrol* or quazicontrol*).ti,ab. or (controlled AND study).ti,ab. or (“pre-post” or “pre post” or “posttest” or “post-test” or “post test” or pretest or “pre-test” or “pre test” or “repeated measure” or “repeated measures”).ti,ab. or (before AND after).ti,ab. or (before AND during).ti,ab. or (“time series” AND interrupt*).ti,ab. or (“time points” AND (multiple or one or two or three or four or five or six or seven or eight or nine or ten or month or monthly or day or daily or week or weekly or hour or hourly)).ti,ab. | 1,286,126
#8; combining | 6 and 7 | 3,077
#9; Exclusions – study designs | 8 not (exp Case Report/ or (0200 or 0700 or 0750 or 1400).md. or (0120 or 0200 or 0240 or 0280 or 0300 or 0400 or 0500).pt.) | 2,045
#10; Exclusions – animal-only | 9 not (animal.po. not human.po.) | 2,044

Database: CINAHL Complete (via EBSCO)

Search date: 9/7/2022

Search Set | Search Strategy | Results
#1; Parenting skills training terms | (((TI parent OR AB parent) OR (TI parents OR AB parents) OR (TI parental OR AB parental) OR (TI parenting OR AB parenting)) N6 ((TI training OR AB training) OR (TI trainings OR AB trainings) OR (TI skill OR AB skill) OR (TI skills OR AB skills) OR (TI education OR AB education) OR (TI educational OR AB educational) OR (TI intervention OR AB intervention) OR (TI interventions OR AB interventions) OR (TI interventional OR AB interventional) OR (TI program OR AB program) OR (TI programs OR AB programs) OR (TI programme OR AB programme) OR (TI programmes OR AB programmes) OR (TI programming OR AB programming) OR (TI course OR AB course) OR (TI courses OR AB courses) OR (TI workshop OR AB workshop) OR (TI workshops OR AB workshops))) OR ((TI “triple P” OR AB “triple P”) OR (TI “positive parenting program” OR AB “positive parenting program”) OR (TI “positive parenting programs” OR AB “positive parenting programs”)) | 25,903
#2; Psychological trauma terms | (MH “Stress Disorders, Post-Traumatic+”) OR (MH “Psychological Trauma+”) OR (MH “Sexual Trauma”) OR (MH “Domestic Violence+”) OR (MH “Intimate Partner Violence”) OR (MH “Gender-Based Violence”) OR (MH “Stalking”) OR (MH “Rape”) OR ((TI trauma OR AB trauma) OR (TI traumas OR AB traumas) OR (TI traumatic OR AB traumatic) OR (TI psychotrauma OR AB psychotrauma) OR (TI psychotraumatic OR AB psychotraumatic) OR (TI PTSD OR AB PTSD) OR (TI posttraumatic OR AB posttraumatic) OR (TI post-traumatic OR AB post-traumatic) OR (TI “combat disorder” OR AB “combat disorder”) OR (TI “combat disorders” OR AB “combat disorders”) OR (TI stalking OR AB stalking) OR (TI stalker OR AB stalker) OR (TI stalkers OR AB stalkers) OR (TI rape OR AB rape) OR (TI rapes OR AB rapes) OR (TI raped OR AB raped)) OR (((TI sex OR AB sex) OR (TI sexual OR AB sexual) OR (TI sexually OR AB sexually) OR (TI domestic OR AB domestic) OR (TI “intimate partner” OR AB “intimate partner”) OR (TI “intimate partners” OR AB “intimate partners”) OR (TI spouse OR AB spouse) OR (TI spouses OR AB spouses) OR (TI spousal OR AB spousal) OR (TI physical OR AB physical) OR (TI physically OR AB physically)) N2 ((TI abuse OR AB abuse) OR (TI abuses OR AB abuses) OR (TI abused OR AB abused) OR (TI abuser OR AB abuser) OR (TI abusers OR AB abusers) OR (TI violence OR AB violence) OR (TI assault OR AB assault) OR (TI assaults OR AB assaults) OR (TI assaulted OR AB assaulted))) OR (((TI psychological OR AB psychological) OR (TI psychologically OR AB psychologically) OR (TI psychologic OR AB psychologic)) N2 ((TI aggression OR AB aggression) OR (TI aggressor OR AB aggressor) OR (TI aggressors OR AB aggressors) OR (TI injury OR AB injury) OR (TI injuries OR AB injuries) OR (TI abuse OR AB abuse) OR (TI abuses OR AB abuses) OR (TI abusive OR AB abusive))) | 208,759
#3; Military / veterans terms | (MH “Military Personnel+”) OR (MH “Veterans+”) OR (MH “Hospitals, Veterans”) OR (MH “Military Deployment+”) OR (MH “Military Family”) OR (MH “Military Medicine”) OR (MH “Military Health”) OR (MH “Military Health Services”) OR (MH “Military Nursing”) OR ((TI veteran OR AB veteran) OR (TI veterans OR AB veterans) OR (TI military OR AB military) OR (TI army OR AB army) OR (TI navy OR AB navy) OR (TI naval OR AB naval) OR (TI marine OR AB marine) OR (TI marines OR AB marines) OR (TI “service member” OR AB “service member”) OR (TI “service members” OR AB “service members”) OR (TI “service men” OR AB “service men”) OR (TI servicemen OR AB servicemen) OR (TI “service women” OR AB “service women”) OR (TI servicewomen OR AB servicewomen) OR (TI postdeployment OR AB postdeployment) OR (TI post-deployment OR AB post-deployment) OR (TI “post deployment” OR AB “post deployment”) OR (TI “after deployment” OR AB “after deployment”)) | 70,139
#4; Mental illness terms | (MM “Mental Disorders”) OR (MH “Mental Disorders, Chronic”) OR (MH “Personality Disorders+”) OR (MH “Antisocial Personality Disorder”) OR (MH “Borderline Personality Disorder”) OR (MH “Compulsive Personality Disorder”) OR (MH “Histrionic Personality Disorder”) OR (MH “Schizotypal Personality Disorder”) OR (MH “Psychotic Disorders”) OR (MH “Bipolar Disorder+”) OR (MH “Affective Disorders, Psychotic+”) OR (MH “Paranoid Disorders”) OR (MH “Postpartum Psychosis”) OR (MH “Schizophrenia+”) OR ((TI “mental illness” OR AB “mental illness”) OR (TI “mental illnesses” OR AB “mental illnesses”) OR (TI “mentally ill” OR AB “mentally ill”) OR (TI “psychiatric illness” OR AB “psychiatric illness”) OR (TI “psychiatric illnesses” OR AB “psychiatric illnesses”) OR (TI “psychiatric disorder” OR AB “psychiatric disorder”) OR (TI “psychiatric disorders” OR AB “psychiatric disorders”) OR (TI “mental disorder” OR AB “mental disorder”) OR (TI “mental disorders” OR AB “mental disorders”) OR (TI “mood disorder” OR AB “mood disorder”) OR (TI “mood disorders” OR AB “mood disorders”) OR (TI depression OR AB depression) OR (TI depressive OR AB depressive) OR (TI bipolar OR AB bipolar) OR (TI schizophrenia OR AB schizophrenia) OR (TI schizophrenic OR AB schizophrenic) OR (TI schizophreniform OR AB schizophreniform) OR (TI schizoaffective OR AB schizoaffective) OR (TI schizo-affective OR AB schizo-affective) OR (TI “schizo affective” OR AB “schizo affective”) OR (TI schizoid OR AB schizoid) OR (TI schizoidism OR AB schizoidism) OR (TI schizotypal OR AB schizotypal) OR (TI schizo-typal OR AB schizotypal) OR (TI “schizo typal” OR AB “schizo typal”) OR (TI psychotic OR AB psychotic) OR (TI psychosis OR AB psychosis) OR (TI psychoses OR AB psychoses) OR (TI mania OR AB mania) OR (TI manic OR AB manic) OR (TI psychopath OR AB psychopath) OR (TI psychopaths OR AB psychopaths) OR (TI psychopathy OR AB psychopathy) OR (TI psychopathic OR AB psychopathic) OR (TI paranoia OR AB paranoia) OR (TI paranoid OR AB paranoid) OR (TI “personality disorder” OR AB “personality disorder”) OR (TI “personality disorders” OR AB “personality disorders”)) OR (((TI antisocial OR AB antisocial) OR (TI borderline OR AB borderline) OR (TI compulsive OR AB compulsive) OR (TI obsessive OR AB obsessive) OR (TI histrionic OR AB histrionic)) N2 ((TI disorder OR AB disorder) OR (TI disorders OR AB disorders))) | 305,707
#5; Combining | S2 OR S3 OR S4 | 547,452
#6; Combining | S1 AND S5 | 3,961
#7; Study Design: EPOC filter or RCTs | (ZT “randomized controlled trial”) OR (MH “Randomized Controlled Trials”) OR (MH “Double-Blind Studies”) OR (MH “Prospective Studies+”) OR (MH “Single-Blind Studies”) OR (MH “Triple-Blind Studies”) OR (MH “Crossover Design”) OR (MH “Experimental Studies”) OR (MH “Clinical Trials”) OR (MH “Intervention Trials”) OR (MH “Preventive Trials”) OR (MH “Therapeutic Trials+”) OR (MH “Controlled Before-After Studies”) OR (MH “Interrupted Time Series Analysis”) OR (MH “Nonrandomized Trials”) OR (MH “Quasi-Experimental Studies+”) OR (MH “Multiple Time Series”) OR (MH “Time Series”) OR (MH “Repeated Measures”) OR ((TI randomized OR AB randomized) OR (TI randomised OR AB randomised) OR (TI randomization OR AB randomization) OR (TI randomisation OR AB randomisation) OR (TI placebo OR AB placebo) OR (TI randomly OR AB randomly) OR (TI trial OR AB trial) OR (TI trials OR AB trials) OR (TI groups OR AB groups) OR (TI “evaluation study” OR AB “evaluation study”) OR (TI “evaluation studies” OR AB “evaluation studies”) OR (TI “intervention study” OR AB “intervention study”) OR (TI “intervention studies” OR AB “intervention studies”) OR (TI cohort OR AB cohort) OR (TI cohorts OR AB cohorts) OR (TI longitudinal OR AB longitudinal) OR (TI longitudinally OR AB longitudinally) OR (TI prospective OR AB prospective) OR (TI prospectively OR AB prospectively) OR (TI “follow up” OR AB “follow up”) OR (TI follow-up OR AB follow-up) OR (TI followup OR AB followup) OR (TI “comparative study” OR AB “comparative study”) OR (TI “comparative studies” OR AB “comparative studies”) OR (TI nonrandom OR AB nonrandom) OR (TI non-random OR AB non-random) OR (TI nonrandomized OR AB nonrandomized) OR (TI non-randomized OR AB non-randomized) OR (TI nonrandomised OR AB nonrandomised) OR (TI non-randomised OR AB non-randomised) OR (TI quasiexperiment* OR AB quasi-experiment*) OR (TI quazi-experiment* OR AB quazi-experiment*) OR (TI quasiexperiment* OR AB quasiexperiment*) OR (TI quaziexperiment* OR AB quaziexperiment*) OR (TI quasirandom* OR AB quasirandom*) OR (TI quazirandom* OR AB quazirandom*) OR (TI quasi-random* OR AB quasi-random*) OR (TI quazi-random* OR AB quazi-random*) OR (TI quasi-control* OR AB quasi-control*) OR (TI quazicontrol* OR AB quazi-control*) OR (TI quasicontrol* OR AB quasicontrol*) OR (TI quazicontrol* OR AB quazicontrol*)) OR ((TI controlled OR AB controlled) AND (TI study OR AB study)) OR ((TI pre-post OR AB prepost) OR (TI “pre post” OR AB “pre post”) OR (TI posttest OR AB posttest) OR (TI post-test OR AB post-test) OR (TI “post test” OR AB “post test”) OR (TI pretest OR AB pretest) OR (TI pre-test OR AB pre-test) OR (TI “pre test” OR AB “pre test”) OR (TI “repeated measure” OR AB “repeated measure”) OR (TI “repeated measures” OR AB “repeated measures”)) OR ((TI before OR AB before) AND (TI after OR AB after)) OR ((TI before OR AB before) AND (TI during OR AB during)) OR ((TI “time series” OR AB “time series”) AND (TI interrupt* OR AB interrupt*)) OR ((TI “time points” OR AB “time points”) AND ((TI multiple OR AB multiple) OR (TI one OR AB one) OR (TI two OR AB two) OR (TI three OR AB three) OR (TI four OR AB four) OR (TI five OR AB five) OR (TI six OR AB six) OR (TI seven OR AB seven) OR (TI eight OR AB eight) OR (TI nine OR AB nine) OR (TI ten OR AB ten) OR (TI month OR AB month) OR (TI monthly OR AB monthly) OR (TI day OR AB day) OR (TI daily OR AB daily) OR (TI week OR AB week) OR (TI weekly OR AB weekly) OR (TI hour OR AB hour) OR (TI hourly OR AB hourly))) | 2,073,422
#8; combining | S6 AND S7 | 2,283
#9; Exclusions – study designs | S8 NOT PT ( Abstract OR Algorithm OR Anecdote OR Bibliography OR Biography OR Book OR Book Chapter OR Book Review OR Cartoon OR Case Study OR Commentary OR Editorial OR Letter OR Masters Thesis OR Doctoral Dissertation OR Forms OR Games OR Pamphlet OR Pamphlet Chapter OR Poetry ) | 2,131
#10; Exclusions – animal-only | S9 NOT (((MH “Animals+”) OR (MH “Animal Studies”) OR (TI “animal model*”)) NOT (MH “human”)) | 2,131