# ABBREVIATIONS TABLE

Abbreviation: Definition
ADAPT: After Deployment, Adaptive Parenting Tools
BPD: Borderline personality disorder
COE: Certainty of evidence
ESP: Evidence Synthesis Program
FOCUS-EC: Families OverComing Stress-Early Childhood
GRADE: Grading of Recommendations Assessment, Development, and Evaluation
KQ: Key question
MDD: Major depressive disorder
OECD: Organization for Economic Co-operation and Development
OEF: Operation Enduring Freedom
OIF: Operation Iraqi Freedom
OND: Operation New Dawn
OPPT: Online Parenting Pro-Tips
PMTO: Parent Management Training–Oregon Model
PSI: Parenting Stress Index
PTSD: Posttraumatic stress disorder
RCT: Randomized controlled trial
ROB: Risk of bias
ROBINS-I: Risk of Bias in Nonrandomized Studies of Interventions
SMI: Serious mental illness
SPMI: Serious and persistent mental illness
STAIR: Skills Training in Affective and Interpersonal Regulation
VA: Veterans Affairs
VHA: Veterans Health Administration