# References

1 Patient Centered Management Module (PCMM) for Primary Care. 2017.
2 Huang PY, Yano EM, Lee ML, Chang BL, Rubenstein LV. Variations in nurse practitioner use in Veterans Affairs primary care practices. Health services research. 2004;39(4 Pt 1):887–904.15230933
3 Alexander GC, Kurlander J, Wynia MK. Physicians in retainer ("concierge") practice. A national survey of physician, patient, and practice characteristics. Journal of general internal medicine. 2005;20(12):1079–1083.16423094
4 Starfield B, Shi L, Macinko J. Contribution of primary care to health systems and health. Milbank Q. 2005;83(3):457–502.16202000
5 Quality AfHRa. Six Domains of Health Care Quality. 2018; http://www.ahrq.gov/talkingquality/measures/six-domains.html. Accessed 5/7/2019.
6 group Gw. 2014; http://www.gradeworkinggroup.org/. Accessed 5/7/2019.
7 Kamnetz S, Trowbridge E, Lochner J, Koslov S, Pandhi N. A Simple Framework for Weighting Panels Across Primary Care Disciplines: Findings From a Large US Multidisciplinary Group Practice. Quality management in health care. 2018;27(4):185–190.30260924
8 Stefos T, Burgess JF, Jr., Mayo-Smith MF, . The effect of physician panel size on health care outcomes. Health services management research. 2011;24(2):96–105.21471580
9 Mohr DC, Benzer JK, Young GJ. Provider Workload and Quality of Care in Primary Care Settings Moderating Role of Relational Climate. Medical care. 2013;51(1):108–114.23222471
10 Katz DA, McCoy K, Sarrazin MV. The Relationship between Pcp Panel Size and Continuity of Va Primary Care. Journal of general internal medicine. 2013;28:S219–S219.
11 CD H, JA S, Clinton WL, . The Association of Team-Specific Workload and Staffing with Odds of Burnout Among VA Primary Care Team Members. J Gen Intern Med. 2017;32(7):760–766.28233221
12 Dahrouge S, Hogg W, Younger J, Muggah E, Russell G, Glazier RH. Primary Care Physician Panel Size and Quality of Care: A Population-Based Study in Ontario, Canada. Annals of family medicine. 2016;14(1):26–33.26755780
13 Mittelstaedt TS, Mori M, Lambert WE, Saultz JW. Provider practice characteristics that promote interpersonal continuity. Journal of the American Board of Family Medicine : JABFM. 2013;26(4):356–365.23833149
14 Margolius D, Gunzler D, Hopkins M, Teng K. Panel Size, Clinician Time in Clinic, and Access to Appointments. Annals of family medicine. 2018;16(6):546–548.30420370
15 Angstman KB, Horn JL, Bernard ME, . Family Medicine Panel Size with Care Teams: Impact on Quality. Journal of the American Board of Family Medicine : JABFM. 2016;29(4):444–451.27390375
16 Francis MD, Zahnd WE, Varney A, Scaife SL, Francis ML. Effect of number of clinics and panel size on patient continuity for medical residents. Journal of graduate medical education. 2009;1(2):310–315.21975997
17 Bredfeldt CE, Compton-Phillips AL, Snyder MH. Effects of between visit physician-patient communication on Diabetes Recognition Program scores. International journal for quality in health care : journal of the International Society for Quality in Health Care. 2011;23(6):664–673.
18 Edwards ST, Marino M, Balasubramanian BA, . Burnout among primary care providers and staff in small to medium sized primary care practices: Early findings from evidence now. Journal of general internal medicine. 2017;32(2):S132.
19 Margolius D, Siff J, Teng K, Einstadter D, Gunzler D, Bolen S. What factors contribute to inbox volume in primary care? Journal of general internal medicine. 2018;33(2):398.
20 Dahrouge S, Hogg WE, Russell G, . Impact of remuneration and organizational factors on completing preventive manoeuvres in primary care practices. CMAJ : Canadian Medical Association journal = journal de l’Association medicale canadienne. 2012;184(2):E135–143.
21 Ward CE, Ashburner JM, Chang Y, Atlas SJ. Relationship between patient experience of care and physician productivity measures. Journal of general internal medicine. 2012;27:S296.
22 Zeng B, Zhao H, Lawley M. The impact of overbooking on primary care patient no-show. IIE Transactions on Healthcare Systems Engineering. 2013;3(3):147–170.
23 Baker R, Bankart MJ, Rashid A, . Characteristics of general practices associated with emergency-department attendance rates: a cross-sectional study. BMJ quality & safety. 2011;20(11):953–958.
24 Altschuler J, Margolius D, Bodenheimer T, Grumbach K. Estimating a reasonable patient panel size for primary care physicians with team-based task delegation. Annals of family medicine. 2012;10(5):396–400.22966102
25 Balasubramanian H, Banerjee R, Denton B, Naessens J, Stahl J. Improving clinical access and continuity through physician panel redesign. Journal of general internal medicine. 2010;25(10):1109–1115.20549379
26 Green LV, Savin S, Murray M. Providing timely access to care: what is the right patient panel size? Joint Commission journal on quality and patient safety. 2007;33(4):211–218.17441559
27 Ozen A, Balasubramanian H. The impact of case mix on timely access to appointments in a primary care group practice. Health care management science. 2013;16(2):101–118.23076360
28 Rajkomar A, Yim JW, Grumbach K, Parekh A. Weighting Primary Care Patient Panel Size: A Novel Electronic Health Record-Derived Measure Using Machine Learning. JMIR medical informatics. 2016;4(4):e29.27742603
29 Balasubramanian H, Banerjee R, Gregg M, Denton BT. Improving primary care access using simulation optimization. In: Proceedings of the 2007 Winter Simulation Conference, Vols 1–5. New York: Ieee; 2007:1473–1479.
30 Zacharias C, Armony M. Joint Panel Sizing and Appointment Scheduling in Outpatient Care. Manage Sci. 2017;63(11):3978–3997.
31 Rossi M, Balasubramanian H. Panel Size, Office Visits, and Care Coordination Events: A New Workload Estimation Methodology Based on Patient Longitudinal Event Histories. MDM Policy & Practice. 2018;3(2).
32 D G. Determination of primary care panel size in a value based compensation health care delivery environment. In:2013.
33 Balasubramanian H, Denton BT, Lin QM. Managing physician panels in primary care. In: Handbook of Healthcare Delivery Systems. CRC Press; 2016:10.
34 Balasubramanian H, Muriel A, Ozen A, Wang L, Gao X, Hippchen J. Capacity Allocation and Flexibility in Primary care. In. International Series in Operations Research and Management Science. Vol 184: Springer New York LLC; 2013:205–228.
35 Murray M, Davies M, Boushon B. Panel size: how many patients can one doctor manage? Family practice management. 2007;14(4):44–51.
36 Murray M, Berwick DM. Advanced access: reducing waiting and delays in primary care. Jama. 2003;289(8):1035–1040.12597760
37 Gupta R, M K. Toolkit for empanelment in teaching clinics. 2018.
38 Newman S, Nguyen D, Fisher T, O’Brien M, Leibig-Shepherd C, D H. CP3 population health toolkit. 2017.
39 Chung S, Eaton LJ, Luft HS. Standardizing primary care physician panels: is age and sex good enough?. The American journal of managed care. 2012;18(7):e262–268.22823555
40 Sinsky C, Colligan L, Li L, . Allocation of Physician Time in Ambulatory Practice: A Time and Motion Study in 4 Specialties. Ann Intern Med. 2016;165(11):753–760.27595430
41 Farber J, Siu A, Bloom P. How much time do physicians spend providing care outside of office visits? Ann Intern Med. 2007;147(10):693–698.18025445
42 Doerr E, Galpin K, Jones-Taylor C, . Between-Visit Workload in Primary Care. Journal of general internal medicine. 2010;25(12):1289–1292.20700665
43 Baron RJ. What’s keeping us so busy in primary care? A snapshot from one practice. N Engl J Med. 2010;362(17):1632–1636.20427812