# Acknowledgments

This topic was developed in response to a nomination by Karin Nelson, Director of the Office of Primary Care’s Analytics Team (PCAT) and Primary Care Physician, for the purpose of supporting policy decisions in the Office of Primary Care regarding panel sizes for primary care providers. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors gratefully acknowledge Roberta Shanman, MLS and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend Technical Expert Panel (TEP) participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Karin Nelson, MD, MSHS
  Director of the Office of Primary Care’s Analytics Team, Primary Care Physician
  VA Puget Sound Health Care System

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Steve Pizer, PhD
  Partnered Evidence-Based Policy Resource Center
  VA Boston Healthcare System Research & Development
- Kevin Dorrance, MD, FACP
  Docsnap, TransformCare, Inc.,
  Uniformed Services University of the Health Sciences
- Lisa V. Rubenstein, MD, MSPH, FACP
  Professor of Medicine and Public Health
  VA Greater Los Angeles and UCLA
  Director, VA HSRD Center for Implementation Practice and Research Support
  Senior Scientist, RAND
- Todd Wagner, PhD
  Director, Health Economics Resource Center
  Associate Director, Center for Innovation to Implementation
  VA Palo Alto Health Care System
  Associate Professor, Department of Surgery, Stanford University School of Medicine

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.