# Summary and Discussion

The evidence about the effect of panel size on the Institute of Medicine aims for health care improvement is surprisingly thin, given the importance of primary care panel size to all models of population-based care. The evidence consists of a handful of cross-sectional studies that assess associations of panel size with clinical quality, patient experience, access and continuity, and show variable, no, or negative associations of increasing panel size on these outcomes of interest. One additional cross-sectional study found an association between larger panel size and physician burnout. By their design these studies cannot support conclusions about increasing panel size being the cause of any differences in outcomes. These studies at best act a signal that there might be causal relationships between larger panel size and worse clinical quality, worse patient experience, and provider burnout. The remainder of the evidence consists of a handful of studies that try and model what should be an optimal panel size, where “optimal” is defined exclusively by access. The modeling studies make the assumption that every additional patient added to a panel is going to be delivered with equal quality and patient-centeredness regardless of the number. The cross-sectional studies we identified provide a signal that this assumption may not be correct. What does seem clear from the modeling studies is that simple models developed years ago, which basically take the number of visits made by existing patients and the number of appointment slots available to determine the panel size, can be improved. Not all patients require the same amount of time, and risk-adjusted methods tested vary from simple (age and gender) to complex (number of health care conditions, number of medications, and more). Furthermore, the resources available to the primary care provider influence how many patients can be cared for – resources such as the number of rooms available to see patients, the ability to delegate tasks to advanced practice providers, and the availability of clinical staff such as RN managers. Lastly, since the early models were developed there has been a plethora of new developments in health care that will influence how many patients can be cared for, such as the rise of non-face-to-face visits, telehealth, and the use of secure messaging, along with a much greater load of information the primary care provider needs to process, and be accountable for. An incomplete list of the non-face-to-face tasks that any assessment of provider capacity includes:

1. Non-face-to-face interactions (with patients)
  a. Telephone calls
  b. E-visits or telemedicine
  c. Secure messaging or email communication
  d. Medication refills
  e. Opioid Initiative
  f. Results letters
2. Complex Care Coordination
  a. Care in the Community review/coordination
  b. Coordination with subspecialty clinics
  c. MISSION Act (consult placement and expanded care coordination)
3. Form Completion
  a. State disability
  b. DMV forms
  c. Aid and Attendance
  d. In support of letters
  e. Dental clearance
  f. Pre-op evaluation
  g. Death certificates

These non-face-to-face tasks take up an increasing amount of clinician time. One study, although it is already based on data nearly 4 years old, followed 57 physicians in 4 practices over approximately 1 month in 2015, and recorded the time it took for various tasks.^40^ This study concluded that for every hour in direct clinical face time with patients, almost 2 additional hours are needed to complete electronic health record and desk work, and that physicians spend 1–2 hours per evening doing additional computer and clerical work. This burden of work outside of the standard “appointment slot” is further supported by data from Farber and colleagues, who found that a full-time PCP would spend an extra 7.8 hours of time per week outside of scheduled appointments caring for their patient panel.^41^ Doerr and colleagues similarly noted that in caring for a VA patient panel, PCPs added an additional 7.9 hours of work per week between visits.^42^ Baron studied his own practice over 1 year and determined, when averaged over the whole panel, each patient in the panel generated 2.0 face-to-face visits, 2.6 telephone calls, 1.3 prescription refills outside of a visit, 1.8 emails, 2.1 laboratory reports, 1.2 imaging reports, and 1.5 reviews of a consultation.^43^

## Summary of Evidence by Key Question

### Key Question 1A How should panel size be determined for a primary care provider?

We cannot answer this question with an evidence review, since “how should…” is a question for policymakers.

### Key Question 1B What is the optimal size of a patient panel in primary care?

There is a modest literature of observational studies, all but 1 being cross-sectional, that assess the relationship between panel size and outcomes of interest. The greatest number of studies assess the IOM aim of timely care, either as access or continuity. In general, these studies found variable access results, some reporting better access, others reporting worse access. Continuity seems to be little affected. There were fewer studies assessing the association between panel size and clinical quality and between panel size and patient experience (3 studies each). In general, these studies showed negative statistically significant relationships of modest size, or no statistically significant relationship, between increasing panel size and various measures of clinical quality and patient experience. One study reported 1 clinical quality measure that had better performance associated with increased panel size. Only 1 study assessed the relationship between panel size and cost and found no statistically significant association. We did not identify any studies assessing the association of panel size as the primary explanatory variable and patient safety and equity. One study found an association between higher panel size and physician burnout.

The modeling studies identified have varied in how they used or estimated important variables, such as predictors of patient demand, the source of the estimates for those predictors of demand, whether the demand is stochastic or not, and the optimization technique used. All models are optimizing some measure of access or continuity, and have either explicitly or implicitly assumed that other aims for health care improvement, such as clinical quality or patient experience, are equivalent with changes in panel size. A consistent finding from the modeling studies is that the optimal panel size for measures of access changes when patient complexity is considered.

### Key Question 1C Is there evidence to suggest that MD, NP and PAs should have different panel sizes?

We found no empirical evidence to inform this question in the published or gray literature.

### Key Question 1D Is there evidence from large health systems in terms of setting and maintaining panel sizes?

We identified no evidence per se on this topic. The only evidence from large health systems we identified were 2 studies that assessed the cross-sectional association of panel size with access and clinical quality, one study from the Mayo Clinic and the other from MetroHealth in Ohio. But neither study discussed how panel sizes are set or maintained. We note this information must exist; it is just likely not published, and therefore it would require written requests or interviews with the relevant officials from large health systems. One additional study came from the English National Health Service, which assessed the association of panel size with emergency department use, but again did not discuss how panel sizes are set or maintained.

### Key Question 2 Should primary care panel sizes be risk-adjusted for patient complexity? If yes, how should risk adjustment be accomplished?

A consistent finding of the modeling studies is that the optimal panel size for measures of access is sensitive to risk adjustment for patient complexity. Which method of adjustment – varying from a simple method that includes age, gender, and insurance status to a complex method that includes many patient health status and prior utilization variables collected from the electronic health record – is “better” has not been tested in head-to-head comparisons, other than to conclude that even the simple method is an improvement over a method that considers just age and gender.

## Limitations

The primary limitation to this review is the paucity of hypothesis-testing studies on the subject. Cross-sectional studies such as those identified in this review have only a very limited ability to support causal conclusions. A second limitation is the possibility of publication bias, particularly for studies where panel size was not the primary explanatory variable, but was something tested as part of a multivariable regression analysis. Such situations have been shown to be prone to publication bias, as investigators only report the results for secondary variables that they consider to be “interesting.” For the association of panel size with access, results were heterogeneous, further limiting the ability to draw conclusions.

### Applicability of Findings to the VA Population

Four of the studies identified were done in VA populations and therefore are directly relevant to VA. However, even these studies use VA data that are 5–10 years old, and primary care delivery in VA has been changing rapidly (for example, PACT), suggesting that the results of these VA studies may already be out of date. It is also important to note that many non-VA studies assume that beneficiaries of a commercial insurance plan or Medicare will primarily use that insurance. This is not necessarily the case in the VA, as Veterans receive care in the VA as an entitlement, not as an insurance benefit. It is therefore possible that they also have another primary insurer, and another primary care physician. How this may influence VA primary care provider panel sizes is unclear.

## Research Gaps/Future Research

A substantial amount of research is needed before declarations of what constitutes an “optimal” panel size in primary care can claim to be evidence-based. VA is well-positioned to conduct this research, due to the existing availability of its rich sources of data. First, more evidence needs to be accumulated about the effect of changes in panel size on the IOM aims other than access. One first step is assessing this within VA by using clinical quality and patient experience outcomes that are collected as part of Strategic Analytics for Improvement and Learning (SAIL) – for example, the individual measures of cancer screening, vaccination, tobacco use, diabetes and hypertension, and the patient experience measures taken from SHEP. Primary care panel size could be collected from the Patient Centered Management Module (PCMM) (in other words, not the SAIL star rating itself, but the unweighted values for the clinical quality and patient experience measures). Analyses could be either cross-sectional, or even longitudinal. The unit of analysis could be at the facility level (as SAIL is currently reported, and would then use average PCP panel size) but would ideally be at the individual PCP level within facility, which would require the SAIL measures at the individual provider level. This would require more resources, but nevertheless these data are already being collected routinely within VA and therefore no new apparatus for data collection or system manipulation is needed. A next step up from this would be an assessment of experimental changes in panel size on clinical quality, access, patient experience, etcetera, and burnout. This would involve intentional changes in panel size – say an increase or decrease of 20% – being applied to existing PCP panels, and then a comparison being made of outcomes to practitioners whose panel sizes remained unchanged, using a difference-indifference analysis, at the end of 1 year. A third line of research could focus on risk adjusting. It is a consistent finding in the modeling studies that risk adjusting improves optimization of access, but the question is which approach works best in VA populations. For example, we could hypothesize that the variability in case mix is larger for the non-VA populations that have been the subject of these studies than it is for VA populations, in which case risk adjustment may make less difference in VA primary care clinics. One way to start is to take the risk adjustment models developed by Rajkomar and colleagues and use VA data from CPRS to see how what proportion of patients fall into their 7 phenotypes.^28^ It may turn out that the great majority of VA patients are clustered in their highest-use phenotypes, in which case the added value of risk adjustment diminishes. Lastly, primary care provider burnout is a priority in VA and non-VA health care systems, and the effect of changes in panel size on burnout need evaluation.

More fundamentally, evidence is needed about the appropriate visit frequency or follow-up time, and format (face-to-face, video or telephone, or secure messaging), for patients with chronic conditions. Most currently used visit frequencies or follow-up times (such as a visit frequency of twice a year for a patient with well-controlled diabetes and hypertension) are based on historical norms, are variable between physicians, and lack evidence that the particular frequency produces better outcomes than some other frequency. Thus, panel size calculations that take a provider’s current patients and uses their prior year’s number of visits in order to calculate what size panel the provider can care for simply perpetuate historical provider-specific variability in visit frequency. Having evidence that a particular frequency produces better outcomes will help break through this endogenous reasoning.

In addition, the nationwide adoption of the team-based PACT model may have fundamentally changed the panel capacity that providers are able to manage. Historical panel size norms from several decades ago, like the target panel size of 1,200 patients, may no longer be relevant to current VA practice. Additional research on the relationship between panel size and PACT team-based care is needed.

## Conclusions

The evidence about the effect of panel size on the Institute of Medicine aims for health care improvement is surprisingly thin, given the importance of primary care panel size to all models of population-based care. The few studies available provide a signal that increasing panel size may have an association with modest worsening of clinical quality and patient experience. Several modeling studies exist, but all model only the effect of panel size on access to care, and assume that other IOM aims are constant with increasing panel size. Modeling studies support the policy that risk-adjustment and practice-level variables influence the optimal panel size for access. Current recommendations regarding primary care panel size are based more on historical experience than on evidence.