# Results

## Literature Flow

We identified 448 potentially relevant citations, and found 14 additional articles during reference mining, for a total of 462 articles whose titles were screened. Of these, 385 titles were excluded for lack of relevance to the topic, and 77 were included for abstract screening. From these, a total of 38 abstracts were excluded. Excluded abstracts were categorized as not about panel size (n=17), no original data (n=2), background (n=3), unavailable (n=8), no outcome of interest (n=2), systematic review (n=2), about residents (n=1), not research (n=2), and not about primary care (n=1). This left 60 publications for full-text review, of which 30 publications were excluded for the following reasons: background (n=15), duplicate (n=2), non-systematic review (n=1), not about panel size (n=9), unavailable (n=1), commentary (n=1), and not a predictor (n=1). A full list of studies excluded at full-text review is included in Appendix C. A total of 30 publications were identified at full-text review as meeting initial inclusion criteria. (See Figure 1 below for literature flow.) This included 16 studies hypothesis-testing articles that assessed the association of panel size with an outcome of interest, 11 studies of models, and 3 toolkits. Descriptions of the hypothesis-testing studies and modeling studies are available in the Evidence Tables D and E (Appendix D and Appendix E).

Figure 1 Literature Flow Chart

## KEY QUESTION 1A How should panel size be determined for a primary care provider?

“How should…” is a question for policymakers that requires value judgments that balance multiple factors, and as such is not something that can be answered by an evidence review. In the remaining sections we describe the evidence policymakers can use when making judgments about how should panel size be determined.

## KEY QUESTION 1B What is the optimal size of a patient panel in primary care?

As noted above, questions about optimization require an outcome be chosen to be optimized. Since the important outcome may differ among stakeholders, we discuss here the evidence of the association of panel size with the 6 Institute of Medicine (IOM) aims of health care, plus the aim of reducing provider burnout.

We identified 4 groups of articles. The first group were hypothesis-testing studies for which the primary explanatory variable was panel size and the dependent variable was 1 or more of our outcomes of interest. The second group of studies were hypothesis-testing studies of some other explanatory variable on outcomes of interest, for which the investigators also assessed panel size. We distinguished these 2 groups by whether or not “panel size” (or another word that the authors then defined as panel size, such as “provider workload”) appeared in the title of the paper. If it did, then we considered the study to be a hypothesis-testing study in the first group. If not, we classified the article as belonging to the second group. The third group of studies were those that built models to determine panel size. The fourth group of articles were toolkits. These were not included as evidence per se, since they do not present results of an assessment of panel size on an outcome of interest, but are included as being potentially of interest.

### Hypothesis-testing Studies of Panel Size

We identified 10 studies that had as their stated primary purpose an evaluation of panel size on an outcome of interest. Nine of these studies were cross-sectional studies, and as such have very limited ability to make causal inferences (meaning that differences in panel size are the cause of any differences in observed outcomes). The ninth study is a pre/post study of a new method of constructing panel sizes based on patient characteristics.^7^ Four of the studies were from VA,^8–11^ 1 study was from Canada,^12^ and the remaining 5 studies were from academic health centers.^7,13–16^ The mean or median panel size in 4 of the studies was similar to what is current in VA (panel size = 1,200). In 2 studies the mean panel size was substantially below this value,^13,16^ in 3 studies the lower end of the range of panel sizes was about 1,200 (with upper limits 2, 3, or even 4 times that),^7,12,15^ and in 1 VA study the actual panel size was reported as being above or below the “optimal” panel size.^9^

We now discuss the evidence according to the IOM aims plus our added aim of provider burnout.

#### Safe

No study assessed the relationship between panel size and measures of patient safety.

#### Effective (Clinical Quality)

3 studies assessed the association of panel size on measures of clinical quality.^12,15,17^ In a VA study based on data from 2004, Stefos and colleagues^8^ used multivariable logistic regression to assess the association between panel size (mean = 1206) with 8 measures of clinical quality collected as part of the External Peer Review Program (an independent assessment of VA clinical quality collected at that time mainly via chart review) across all VA. (Additional outcome variables included patient experience and waiting time, discussed below). A number of control variables were included in the model: practitioner type (physician vs non-physician), number of exam rooms, staff FTE, patient age greater than 65, gender, insurance status, distance of the patient to the treating facility, VA priority status, a measure of patient risk, and whether care was in a community-based clinic or other. The results of the multivariable analysis showed that increasing panel size was associated with statistically significantly lower standardized odds of a patient receiving appropriate pneumococcal vaccination and getting an alcohol misuse screen (adjusted odds ratios of 0.95, 95% confidence interval 0.91 to 0.99, and 0.94, 95 confidence interval CI 0.89 to 0.99, respectively). This translates to an estimated 5% decrease in vaccination and a 4% decrease in alcohol screen with an increase in mean panel size from 1,206 by 1 standard deviation to 1,566. Of the other 6 clinical quality measures, 4 had odds ratios of worse care that were not statistically significant (diabetes mellitus patients with A1c <9, hyperlipidemia screen, ischemic heart disease full lipid profile, and diabetes retinal exam), 2 clinical quality measures had an odds ratio of 1.0 (colorectal cancer screen and hypertension blood pressure less than 140/90), and no measures had an odds ratio of better quality with increasing panel size.

In a study from the Family Medicine department of the Mayo Clinic, Angstman and colleagues^15^ assessed the relationship between panel size for 36 clinicians with a composite measure of clinical quality for patients with diabetes (an all-or-none composite of control of A1c, blood pressure, and lipids; additional outcome variables included patient experience, access, and cost, discussed below). The adjusted panel size ranged from 1,876 to 4,828. The analysis was multivariable and adjusted for patient differences using the Hierarchical Conditions Categories (HCC). These authors found increasing panel size negatively associated with diabetes clinical quality (p = 0.03).

The third study^12^ in this group was from Ottawa, Canada, and assessed the relationship between panel size for 4,195 physicians and measures of cancer screening, chronic disease management, admissions for ambulatory care sensitive conditions, and emergency department visits (additional outcome variables assessed were continuity and comprehensiveness, discussed below). These authors excluded from their analysis any clinician with a panel size below 1,200, so panel sizes ranged from 1,200 to more than 3,600. Analyses were adjusted for patient complexity using the Adjusted Clinical Group system. The analysis found that the likelihood of being up-to-date on screening for cervical, breast, or colorectal cancer decreased modestly but statistically significantly as panel size increased (for example from 45.6% screened for colorectal cancer in the lowest panel size practices to 44.4% screening in the highest panel size practices). Six measures of performance for patients with diabetes showed no statistically significant differences across panel sizes. The likelihood of getting an echocardiogram in a patient with heart failure statistically significantly increased with increasing panel size (from 69.4% to 75.5%). Admissions for ambulatory care-sensitive conditions statistically significantly increased with increasing panel sizes (by 1.25 admissions per 10,000 patients) while emergency department visits decreased (from 19.5 to 17.4 per 100 patients). Authors also note that in their fully adjusted model, a panel size of less than 1,600 was associated with a 6.8-point (95% confidence interval 3.1 to 10.6) increase on a 100-point quality scale.

#### Patient-centered

Three studies assessed the association of panel size on patient-centered care, generally measured as patient experience or patient satisfaction.^8,9,15^ Two of these studies have already been described in the section, above, on Effective (Clinical Quality). In the study by Stefos and colleagues,^8^ using 2004 VA data, in the multivariable analysis increasing panel size was associated with worse patient satisfaction, as measured by a response of “very good” or “excellent” to the question “All things considered, are you satisfied with your care?”, although this did not quite reach the conventional level of statistical significance (adjusted odds ratio = 0.96, 95% confidence interval 0.92 to 1.00). In the study by Angstman and colleagues from Mayo Clinic, patient satisfaction, as measured by the top box score in the Avatar patient satisfaction survey, was not associated with differences in panel size.^15^ The third study in this group was another study from VA, using data from 2006–2007. In this study, Mohr and colleagues assessed workload, defined as panel size, with 3 measures of patient experience: complaints, provider time availability during the visit, and overall quality of the visit, all taken from the VA Survey of Healthcare Experiences of Patients (SHEP).^9^ In their multivariable analysis, they controlled for patient characteristics (including age, sex, race, ethnicity, health status as measured by the 12-Item Short Form Health Survey (SF-12), urban versus rural status, teaching hospital status, FTE per clinic, and RN staff per clinic). Workload (panel size) was statistically significantly associated with more patient complaints (adjusted odds ratio = 1.71), worse provider time availability (adjusted odds ratio = 0.61), and fewer positive ratings of overall quality of visit (linear regression estimate = −0.20). Another focus of this analysis was the effect of what the authors term “relational climate”, taken from a 3-item scale in the VA All Employee Survey, about cooperation and respect. The authors found a moderating effect of relational climate in 2 of their 3 analyses.

#### Timely (Access)

Eight of the 9 studies assessed timeliness of care, either measured as access or continuity. In a 2013 study of VA primary care providers in patient-aligned care teams (PACT), Katz and colleagues used multivariable regression to examine the relationship between panel size (median = 1178) and several measures of actual and relational continuity of primary care.^10^ In their models, authors controlled for patient demographics, disability status, 22 chronic medical and psychiatric conditions, number of primary care clinic visits, provider full-time equivalent, provider participation in a PACT Learning Collaborative, and usual site of care. They found no significant relationships between panel size and the Usual Provider Continuity Index (UPC), the Modified Continuity Index, or survey measures of shared decision-making. However, increasing panel size was weakly associated with excellent patient-reported interpersonal communication (OR=1.007).

Also in 2013, Mittelstadt and colleagues found that panel size (mean = 577) among 63 providers in the Oregon Health & Sciences University Department of Family Medicine outpatient clinics was not significantly associated with the UPC.^13^ Their multivariable model contained measures of provider clinic frequency (half-day clinic sessions per month), patient load (ratio of panel size to clinic frequency), years in practice, provider type, and a provider type by patient load interaction.

Next, Kamnetz and colleagues published a study in 2018 evaluating the effect of panel weighting (panel size range: 1,244–2,315 [preweighting]; 949–2,705 [postweighting]) on access among 112 primary care providers in the University of Wisconsin system.^7^ After weighting panels by patient age, sex, and insurance type (Medicare, Medicaid or other), total number of active patients increased (by 2%), but the number of patients who strongly agreed that an appointment in general internal or family medicine was available when needed also significantly increased (from 70%-75% depending on clinic to 75%-80%; p < .05).

In another 2018 study by Margolius and colleagues, a multivariable analysis of the relationship between third next available appointment (TNAA) and panel size (mean = 1,146) was conducted using data from 114 primary care providers in the Ohio MetroHealth System.^14^ After controlling for provider full-time equivalents, and number of providers per site, the authors found that TNAA was positively related to panel size (r = 0.22, p = .032).

Francis and colleagues assessed the number of clinics and panel size on continuity in medical resident clinics.^16^ This study used data from the Southern Illinois School of Medicine teaching clinics, where the mean panel size was 54 patients, and found in multivariable analysis that patient continuity decreased by 1.4% for every 10 additional patients in the medical resident’s panel. This study is of marginal relevance to VA non-teaching clinic care, but could be applicable to setting panel sizes in VA teaching clinics.

The last 3 studies have been previously described in the section on Effective (Clinical Quality). In the study by Stefos and colleagues using VA data, 1 standard deviation increase in panel size was associated with a 2.04 day increase in waiting time (difference between the date scheduled for a primary care appointment and the actual date seen in clinic), but this was not statistically significant.^8^ The study by Angstman and colleagues from the Mayo Clinic found that increasing panel size was statistically significantly associated with longer times to the third next available appointment (p < .01).^15^ In the study from Ottawa, Canada, Dahrouge and colleagues found a shallow, statistically significant U-shaped curvilinear relationship between deciles of panel size and continuity, starting out at 78% of visits with the same provider at the smallest panel size decile, rising to high of 79.3% in the middle decile, and then falling again to a low of 76.7% in the highest decile of panel size.^12^

#### Efficient (Including Cost)

We did not identify any studies that assessed efficiency or cost. One study assessed the relationship between panel size and found no statistically significant effect of panel size on cost of care, as measured by per member per month charges.^15^ However, charges are not a good measure of cost so it was not included here as evidence.

#### Equitable

No study assessed the relationship between panel size and measures of equitable care.

#### Provider Burnout

One cross-sectional study assessed panel size as a primary explanatory variable for physician burnout.^11^ This study assessed 1,517 VA primary care physicians (response rate = 32.9%) who responded to an online survey about their work experience, then linked these data to VA data on primary care workload. Panel overcapacity was defined as having a panel size greater than 1,200 patients adjusted by the number of half-days of clinic worked per week. Physician burnout was measured using a single item self-report measure from the Physician Worklife Study rating the level of burnout on a 5-point scale. In univariate analyses, physician burnout was statistically significantly higher in respondents who had panel sizes overcapacity than those at or undercapacity (53.3% versus 48.0%). In a multivariable analysis controlling for other aspects of practice – such as whether or not their primary care team was fully staffed or working extended hours, the degree of clinic staff turnover, and average patient comorbidity – panel overcapacity had an increased adjusted odds ratio of burnout (adjusted odds ratio = 1.19, 95% confidence interval 1.01 to 1.40).

There were 2 studies in the next group that did include panel size as 1 variable among many that were tested for associations with provider burnout^18,19^ (see below).

#### Summary of Hypothesis-testing Studies of Panel Size

There is a modest literature of observational studies, all but 1 being cross-sectional, that assess the relationship between panel size and outcomes of interest. The greatest number of studies assess the IOM aim of timely care, either as access or continuity. In general, these studies found variable access results, some reporting better access, others reporting worse - access. Continuity seems to be little affected. There were fewer studies assessing the association between panel size and clinical quality and between panel size and patient experience (3 studies each). In general, these studies showed negative statistically significant relationships of modest size, or no statistically significant relationship, between increasing panel size and various measures of clinical quality and patient experience. One study reported 1 clinical quality measure that had better performance associated with increased panel size. No study assessed the relationship between panel size and cost. One study found a cross-sectional relationship between increased panel size and physician burnout. We did not identify any studies assessing the association of panel size and patient safety or equity.

Certainty of Evidence

Outcome | Number of studies | Study limitations | Consistency | Direction of effect | Overall Certainty of Evidence
Safe | 0 | N/A | N/A | N/A | Very Low
Effective (Clinical quality) | 3 | Serious | Mostly consistent | No association or negative association of modest size | Low
Patient-centered | 3 | Serious | Inconsistent | No association or negative associations of modest size | Low
Timely (Access, including Continuity) | 8 | Serious | Inconsistent | Variable | Low
Efficient (including Cost) | 0 | N/A | N/A | N/A | Very Low
Equitable | 0 | N/A | N/A | N/A | Very Low
Provider burnout | 1 | Serious | N/A | Increased physician burnout with panel sizes higher than 1,200 | Very Low

### Hypothesis-testing Studies of Other Questions that Include Panel Size as an Explanatory Variable

We identified 6 studies that were about other questions, but which reported the results of tests of the association of panel size with an outcome of interest. The first of these was from Canada and was focused on the effects of changes in payment (from fee-for-service to salaried or capitation) on the delivery of preventive care services.^20^ This cross-sectional study included 137 primary care practices, about equal numbers of which were in 1 of 4 models of payment (capitation was split into “new” and “established”). The proportion of panel sizes under 1,600 varied from 43% to 85%, depending on payment model. A panel size of less than 1,600 patients was, along with other factors like the use of an electronic reminder system, and the presence of at least 1 female physician, associated with better score on a set of 6 measures (influenza vaccination; cervical, breast, and colorectal cancer screening; visual impairment screening; and auditory impairment screening). The second study, presented in abstract form only, concerned the relationship between physician productivity measures and patient experience.^21^ It assessed 14,587 patients cared for by 156 physicians in 13 primary care practices within the Massachusetts General Hospital practice network, and used data from the Consumer Assessment of Healthcare Providers and Systems as the outcome. The abstract contains 1 line of text, stating “however, increasing panel size was associated with better performance on the communication composite (beta 0.023, p=0.001)”. No additional information relevant to this is presented. Two studies assessed aspects of access. One of these was a modeling study assessing the relationship between overbooking and no-show rates.^22^ In this model, panel size was added as a control variable, since “panel size…directly affects appointment delay”. One conclusion of the model is that “there is a critical panel size range (with and without overbooking) in which both the patient show-up rate and the clinic’s expected profit decreases as the panel size increases.” The second of these access-related studies assessed factors associated with emergency department use in 2 geographic areas of England.^23^ A multivariable analysis found that lower practice size was associated with an increase in use of the emergency department. Lastly, 2 studies assessed aspects of provider burnout. The first of these, presented only in abstract form, notes that “inbox message volumes…account for over an hour of additional work per day” for primary care physicians, and assessed the effect of several variables, including panel size, on inbox volume.^19^ This study found, for 86 PCPs in 19 practices in MetroHealth, that panel size was positively associated with an increase in the number of daily messages (along with patient income and number of days worked in clinic). We included this study in the section on provider burnout because that is how it was framed by the authors, in that their results indicate “the need to ensure sufficient time for health care teams…to address patient care issues that occur outside of the face-to-face visit”. The last of these studies, also presented only in abstract form, assessed the cross-sectional association of panel size and a single item of physician burnout in 1,685 primary care practices in 7 regions of the US.^18^ Although a number of variables were associated with burnout (such as more years in practice and rural location), clinician panel size and patients seen per week were not statistically significantly associated with burnout, although no data were presented beyond that narrative text.

#### Summary of Studies of Other Questions that Include Panel Size

We draw no conclusions from these studies, because they either: are reported only in abstract form and the data available are insufficient to assess it; they concern contexts not relevant to VA primary care (English general practices with very large panel sizes); are cross-sectional in design; use a binary classification of panel size at 1,600 (far above what VA uses as a typical panel size); and have a high likelihood of publication bias for studies like these (in that they would only report panel size if they had a “positive” finding).

### Modeling Studies to Determine Panel Size

We identified 11 studies that created and evaluated models to determine how to optimize panel size in primary care.^24–34^ However, some of the studies are about the same or similar models, so we considered these as 4 distinct models (details of which are presented in Appendix E):

1. UCSF: Altschuler 2012^24^; Rajkomar 2016^28^
2. Mayo Clinic: Balasubramanian 2007^29^; Balasubramanian 2010^25^; Ozen 2013^27^; Rossi 2018^31^; Balasubramanian 2016^33^; Balasubramanian 2013^34^
3. Columbia: Green 2007^26^
4. Florida: Zacharias 2017^30^

The last article we identified (from the gray literature) was a PowerPoint presentation^32^ that examined the effects of various factors when added to a “standard” panel size model calculator (probably similar to what was proposed by Murray and Davies^35^), but is not about calculating optimal panel sizes per se. This PowerPoint presentation concludes that a number of variables, some of them beyond the standard model, can influence panel size calculations, including work hours, workload balance, attribution, no-visit and non-billable encounters, the availability of advance practice providers, and ancillary services. This PowerPoint presentation reports that patient acuity (or comorbidity or risk) “plays a small but perceptible role in observed panel size calculations” for the primary care provider.

Before commenting specifically on the remaining articles, we describe a logic model that underlies the motivations for optimizing panel size. We do so as this then enables us to comment on how each of the articles provide evidence for the various parts of the logic model – and hence where gaps remain – and also to highlight how assumptions in the articles themselves may be important in interpreting their results in light of the goals of optimizing panel size.

#### Logic Model

Elements that will be important in determining optimal panel size include:

1. Patient Demand for PCP Visits and Other Non-Face-to-Face PCP Services/Effort: Demand is a complex function of patient underlying need, the correct recognition of the need by the patient, knowledge gained both via provider advice and other sources, the perceived costs and burdens of attempting to make and attend an appointment or use other services, and the perceived benefits of attending an appointment or using other services.
2. Supply of Available PCP Appointments and Time for Other Non-to-Face PCP Services/Effort: Supply is a complex function of panel size, clinic organization in terms of number and length of available appointments, availability of alternative and complementary non-face-to-face services, type and size of team surrounding the PCP, willingness/availability to handle overflow, and non-clinical demands on staff time.
3. Outcomes: Outcomes include a range of benefits and costs which depend on whether different types of patients are seen and what services they receive when seen (and/or receive services in a non-face-to-face manner) with varying degrees of delay and the degree of burden and burnout of PCPs and other staff in order to achieve a given level of supply at a given panel size and case-mix. The likelihood of positive health outcomes is often proxied by a set of measures surrounding the receipt of appropriate and timely services depending on a patient’s underlying diagnoses/health condition. Additionally, patient experience is taken as an important outcome. There appear to be fewer proxy measures for PCP/staff-related outcomes.
4. Value: Involves the combination of a range of benefits and costs to determine whether, in net, panel size (conditional on other organizational features) is worth the costs. Implicitly or explicitly, this implies that acceptable trade-offs must be understood/specified.

We now proceed to a review of these studies.

#### How Do Studies Model Patient Demand?

Studies use predicted patient demand based on their own analyses of PCP data sets or taken from prior published literature. Some predictions are the same (average) for all patients, while others make predictions conditional on age, sex, or other relevant clinical characteristics. Some studies allow for heterogeneity of demand both across and within patient types as well as stochastic variation in demand.

Importantly, all estimates are made based on purely observational analyses that do not consider change in demand as a function of changes in patient characteristics, panel size, or organization features. Likewise, no studies incorporate potential modification of demand as a patient behavioral response to changes in panel size or other organizational features. The implication of this is that all studies assume that individual patient demand will not change as panel size and other organization features are optimized or changed.

#### What Features of Supply Do Studies Consider?

Studies take various approaches in terms of thinking about how total supply/needed supply can be controlled. All studies consider panel size, some studies consider strategies involving altering case-mix across PCPs within multi-provider practices, and some studies consider various team organizations that include PCPs and other health care professionals who can act at PCP extenders.

Supply is most typically thought of as patient appointment slots with the implicit assumption generally that all appointments are of the same length. Some studies relax this assumption and allow for heterogeneity of appointment length and also consider complementary supply of non-face-to-face services.

#### What Outcomes Do Studies Consider?

Most studies operate under the assumption that all (or the vast majority) of appointments should be offered on the day of the patient call, consistent with various articles by Berwick and colleagues.^36^ This implies that 1 of the main outcomes is ensuring that supply is equal to or greater than demand for appointments that the percentage of days where demand exceeds supply is small, so that backlog is controllable.

Some studies also consider patient waiting time when they arrive at a crowded clinic to receive a same-day appointment.

No studies explicitly consider what services are delivered during appointments (or via non-face-to-face means). Implicitly, this assumes that regardless of organization all necessary/indicated services are delivered within the confines of each appointment. Even though studies often model heterogeneity of demand for appointment as a function of patient age, sex, other clinical characteristics, and/or past usage, they do not consider how supply/lack of supply of appointments may have differentially large benefits/costs for different types of patients. These modeling choices imply that the benefits gained/harms averted by each incremental step towards satisfying patient demand are equal to all other steps. In addition, some studies consider various team organizations.

#### Do Studies Consider Value?

Almost all studies match patient demand to supply without explicitly considering the costs of alternative panel sizes or other organizational structures. This choice supposes that meeting patient demand provides benefits that are much larger than the costs, and hence that maximizing this outcome (and/or closely related outcomes) is the same as maximizing value.

One study explicitly – albeit in abstract terms – attaches costs and rewards (benefits) for the outcomes it considers as a function of panel size and combines these in an optimization framework. Presumably the reward for satisfying each demanded appointment (incidentally not dependent on patient type) is a monetization of the health gains and other benefits that come from a timely appointment.

#### What Approaches Do Studies Use to Conduct Their Analyses/Optimizations?

Some studies consider the total number of work hours that a PCP has available. They typically divide this total into appointment sizes of a fixed length and then determine (given average demand per patient) how many patients could be in the panel.

Other studies use various optimization techniques (analytical approximations or numerical optimization) to find panel sizes, case-mix changes, etcetera, that satisfy the objective(s) they are trying to achieve (eg, low chance that demanded appointments exceed supply of appointments in a given day; short within-clinic waiting times for patients).

#### Findings from Modeling Studies

With the above considerations kept in mind, we now review the findings of the modeling studies.

One of the earliest such modeling studies was published by Green and colleagues in 2007.^26^ The authors describe 6 steps:

1. Identifying the current panel size
2. Estimating the daily visit rate per patient
3. Fixing the number of daily appointment slots
4. Calculating the current overflow frequency
5. Setting the target overflow frequency
6. Computing the panel size based on the target flow frequency

This model was developed in the context of Advanced Access, a model of care which tries to ensure that all patients get seen on the day they present for care. In sample calculations, the authors present the calculated panel size under assumptions about the number of daily appointment slots (20 or 24) and an overflow frequency of 5%, 10%, or 15%. For example, for the 20 slot per day example (which still exceeds the number of slots in most VA primary care practices), with an overflow frequency set low (5%) the calculated panel size was 1,879. With the overflow frequency set high (20%) the calculated panel size was 2,279.

Another early model was published by Balasubramanian, who along with colleagues has published variations and improvements on it over the years.^25,29^ In the first such study, Balasubramanian, Banerjee, and Gregg used data from the primary care clinics at the Mayo Clinic at Rochester to optimize panels on 2 measures of access (the average time a patient waits to see a provider and the number of a patient’s visits that are to his or her own provider) and 1 measure of resource use (the amount of additional capacity needed to be added for each period). The authors reported that their model only used age and gender for case mix adjustment, and they had plans for including more variables to better capture variations in demand. Subsequent versions of their model^27,34^ included more sophisticated case mix adjustment, such as the presence of various chronic conditions, and resulted in better optimization when applied to provider panels of about 1,000 patients, in terms of smoothing out imbalances in demand and improving access. These results led the authors to conclude “we have shown that case-mix is an important consideration in primary care.” Although they concluded that their adjustments would improve access and continuity, in this study they did not recommend an optimal panel size. They did however provide a framework for future development of simulation and optimization modeling to consider differences in demand between patient groups and to address the new changes in team-based care. They also noted that it remained to be evaluated what impact these changes would have on quality of care. In this group’s most recent study,^31^ they further attempted to refine their demand estimation by retrospectively quantifying patterns of face-to-face visits and care coordination events (emergency department visits). They were able to predict the number of weekly appointments needed for panel sizes of 1,500 and 2,000 patients. They stated that it is difficult to quantify the care coordination events, which are often spread across email, chart reviews, telephone calls, conversations, and huddles. They also conclude “As our results confirm…there is no one size fits all to the question [of what is the optimal panel size]. Each physician or care team is likely to have a different size depending on a variety of factors such as case mix, practice style, and available capacity.”

Rajkomar and colleagues also tried to improve the demand calculation by using electronic health record data to classify patients into phenotypes based on the number of their encounters (visits, telephone, electronic messaging, and care coordination).^28^ This allowed them to weight panels based on patient demand and complexity. They concluded that these phenotypes could predict future primary care utilization. With this information, panel sizes could be decreased for more complex patients, or higher utilizers could be spread over different panels. The authors noted that their model did not answer the question of what the “right” weight panel size should be for a given health system.

Lastly, Altschuler and colleagues used a completely different method to calculate optimal panel size.^24^ Rather than take existing data about real patients and their prior demand for care, Altschuler and colleagues estimated the work required to deliver primary care by taking existing published estimates of the time needed to provide preventative care as defined by the US Preventive Services Task Force grade A and B recommendations, the time needed to deliver chronic care for 10 common conditions, and the time needed to deliver acute care, and then calculated how many patients a primary care provider could deliver this care to given a certain number of hours worked per year. They did this calculation for 4 different assumptions of the amount of care that could be delegated to other providers, such as nurse practitioners, registered nurses, pharmacists, and health educators. In the non-delegated model, they determined that a provider could care for a panel of 983 patients. In a fully delegated model, that number could increase to 1,947. Intermediate amounts of delegation produced numbers between these 2 extremes. Of note, their calculations were based on an average case mix, and times per service were estimated and not derived from time-motion studies. In their discussion, the authors stated that VA’s delegated model with a panel size of 1,200 was “reasonable” because the patient population in the VA system is older and has more chronic illnesses than in their modeled analysis.

One additional study used modeling, but this study is discussed elsewhere in this report. Kamnetz and colleagues also used modeling to improve optimal panel sizes by adding insurance status to the age and gender variables used for case mix adjustments.^7^ They used insurance status (Medicare, Medicaid, Other) as “a proxy for patient complexity”. Since this study then assessed in a pre-post fashion the effect of this change in method to calculate panel size, it is discussed above in the “hypothesis-testing” studies section.

#### Summary of Modeling Studies

The modeling studies have varied in how they used or estimated important variables, such as predictors of patient demand, the source of the estimates for those predictors of demand, whether the demand is stochastic or not, and the optimization technique used. All models are optimizing some measure of access or continuity, and have either explicitly or implicitly assumed that other aims for health care improvement, such as clinical quality or patient experience, are equivalent with changes in panel size. A consistent finding from the modeling studies is that the optimal panel size for measures of access changes when patient factors are considered.

### Toolkits

We identified 3 documents that were not hypothesis-testing studies of panel size, but nonetheless seemed of interest as they present toolkits to help practices determine their optimal panel size.

These include:

Family Practice Management Panel Size: How Many Patients Can One Doctor Manage?—This toolkit uses the model developed by Murray and Davies.^35^ It states that the variables that influence panel size are the number of patients seen per day, the number of days the provider is available per year, and the average number of visits per patient per year. It then provides weights to adjust panel size by the patient age and gender.

University of California, San Francisco Toolkit for Empanelment in Teaching Clinics.^37^—This discusses issues particular to teaching clinics with rotating medical trainees. The underlying structure, though, appears to be based on the Murray and Davies model.

CP3 Population Health Toolkit^38^—This toolkit was created for Federally Qualified Health Centers.

## KEY QUESTION 1C Is there evidence to suggest that MDs, NPs, and PAs should have different panel sizes?

We found no empirical evidence to inform this question in the published or gray literature.

## KEY QUESTION 1D Is there evidence from large health systems in terms of setting and maintaining panel sizes?

We identified no evidence per se on this topic. The only evidence from large US health systems we identified were 2 studies (previously discussed) that assessed the cross-sectional association of panel size with access and clinical quality, one study from the Mayo Clinic and the other from MetroHealth in Ohio. But neither study discussed how panel sizes are set or maintained. We note this information must exist; it is just likely not published, and therefore it would require written requests or interviews with the relevant officials from large health systems. One additional study came from the English National Health Service, which assessed the association of panel size with emergency department use (discussed above), but again it did not discuss how panel sizes are set or maintained.^23^

## KEY QUESTION 2 Should primary care panel sizes be risk-adjusted for patient complexity? If yes, how should risk adjustment be accomplished?

This has already been discussed in the section on modeling studies, above. A consistent finding of the modeling studies is that the optimal panel size for measures of access is sensitive to risk adjustment for patient complexity. Which method of adjustment – which has varied from a simple method that includes age, gender and insurance status to a complex method that includes many patient health status and prior utilization variables collected from the electronic health record – is “better” has not been tested in head-to-head comparisons, other than to conclude that even the simple method is an improvement over a method that considers just age and gender. This conclusion is supported by the results of a comparison of age-sex weighting with weighting that includes conditions, as measured by Episode Treatment Groups. Chung and colleagues evaluated workload using relative value unit (RVU) data among both pediatric and adult panels. Typical panel size in their study ranged from 203 to 2,220, with an average of 959.^39^ They found that a patient’s clinical conditions better accounted for differences in workload than did age and gender. They did not determine an optimal panel size, but they concluded that weighting of patients is important because the heterogeneity of individual provider panels needs to be accounted for when determining panel size.

Certainty of Evidence for Risk-adjustment

Outcome | Number of studies | Study limitations | Consistency | Direction of effect | Overall Certainty of Evidence
Access | 5 | Not serious | Consistent | Better optimization when panel sizes are adjusted for case mix | Moderate
Access | 2 | Not serious | Consistent | Risk adjustment that includes clinical conditions is better than risk adjustment with just age and sex in optimizing access | Moderate