# Methods

## Topic Development

This topic was developed in response to a nomination by Karin Nelson, Director for the Office of Primary Care Analytics and primary care physician. Key questions were then developed with input from the topic nominator, the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

The Key Questions were:

- KQ1A. How should panel size be determined for a primary care provider?
- KQ1B. What is the optimal size of a patient panel in primary care?
- KQ1C. Is there evidence to suggest that MDs, NPs, and PAs should have different panel sizes?
- KQ1D. Is there evidence from large health systems in terms of setting and maintaining panel sizes?
- KQ2. Should primary care panel sizes be risk-adjusted for patient complexity? If yes, how should risk adjustment be accomplished?

This review was not registered in PROSPERO because it is not about a health care intervention.

## General Considerations

For this topic, we expected that potentially relevant evidence might be found in the gray literature, and so added gray literature searches to our normal PubMed, Web of Science, Scopus, and Embase searches. We did not consider this the kind of topic for which the Cochrane database was particularly relevant so did not search it. We did not expect this evidence to consist of randomized trials and therefore had no study design inclusion or exclusion criteria, other than that it be a hypothesis-testing study or model to calculate panel size that was explicit about its methods and its findings. Key question requests like “what is the optimal size…” require that there be an outcome measure that is being optimized. However, the choice of outcome measure may be different for different stakeholders, and therefore we did not restrict ourselves to one measure (such as access to care). We used the Institute of Medicine (IOM) framework for quality health care as our source of potential measures that could be considered for optimization.^5^ The IOM framework has 6 aims: safe, effective (which we operationalized to include clinical quality), patient-centered (which included patient experience measures), timely (which we operationalized to include access and continuity), efficient (which we operationalized to include cost), and equitable. To these 6 aims we included the aim of reducing provider burnout.

## Search Strategy

We conducted searches in PubMed from inception to 03/08/2019, Web of Science from inception to 03/10/2019, and Scopus and Embase from inception to 03/08/2019. The searches used “panel size” and “primary health care” as the set of terms. See Appendix A for complete search strategy. We also searched the gray literature, starting with terms like “primary care panel size” in a Google search and then also using the Google-generated search terms “Medical Group Management Association (MGMA) panel size,” “primary care panel size benchmark,” “patient panel size worksheet,” “Kaiser Permanente primary care panel size,” “risk adjusted panel size,” and “primary care practice size.” We looked at the first 20 hits for each search.

## Study Selection

3 team members working independently screened the titles of retrieved citations. For titles deemed relevant by at least 1 person, abstracts were then screened independently in triplicate by team members. All disagreements were reconciled through group discussion. Full-text review was conducted in duplicate by 2 independent team members, with any disagreements resolved through discussion. There was no restriction on study design but publications must have presented research with original data that tested a hypothesis (eg, the association between panel size and an outcome of interest) or with the description of a model to calculate panel size, or be a toolkit to help determine panel size.

## Data Abstraction

Data extraction was completed in duplicate. All discrepancies were resolved with full group discussion. We abstracted data on the following: practitioner type, study design, sample size (number of practices), panel size range, other factors, and outcomes of interest. We considered outcomes of interest to be the 6 Institute of Medicine aims for health care improvement (safe, effective, patient-centered, timely, efficient, equitable) and added to this the aim of reducing provider burnout.

## Quality Assessment

We did not use quality assessment per se, in the sense of a standard tool like the Cochrane Risk of Bias tool. This was because all but 1 of the included hypothesis-testing studies were observational and cross-sectional in design, which we state have limited ability to support causal inferences. Therefore, based on this 1 factor alone the evidence is not coming from high-quality studies. The remaining studies are modeling studies, for which there is no generally accepted tool (such as the Cochrane Risk of Bias tool for randomized trials) to assess model quality. However, we narratively discuss the strengths and limitations of the models in addition to their findings.

## Data Synthesis

The observational studies were too clinically heterogeneous to support meta-analysis; hence, our synthesis is narrative.

## Rating the Body of Evidence

We used criteria similar to those proposed by the Grading of Recommendations Assessment, Development and Evaluation (GRADE) working group.^6^ GRADE assesses the certainty of the evidence based of the assessment of the following domains: risk of bias, imprecision, inconsistency, indirectness, and publication bias. This results in categories as follows:

- High: We are very confident that the true effect lies close to that of the estimate of the effect.
- Moderate: We are moderately confident in the effect estimate. The true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.
- Low: Our confidence in the effect estimate is limited. The true effect may be substantially different from the estimate of the effect.
- Very low: We have very little confidence in the effect estimate. The true effect is likely to be substantially different from the estimate of effect.

## Peer Review

A draft version of the report was reviewed by our technical experts. Reviewer comments and our responses are documented in Appendix B.