# Introduction

In 2009, the Veterans Health Administration Handbook 1101.02 established a baseline panel size of 1,200 patients for a full-time physician in a Patient Aligned Care Team (PACT). This number could be adjusted up or down based on availability of support staff, the number of examination rooms, and patient complexity. After adjustment for these factors, panels ranged in size from 1,000 to 1,400 patients. Veterans Health Administration (VHA) Directive 1406 reaffirmed both the baseline panel numbers and adjustment parameters.^1^

The emergence of the 1,200-patient panel size was based on historical averages at the time, but appears to have its genesis in data collected in 2004 by Huang and colleagues, which noted an average full-time VA physician panel size of 1,265 patients.^2^ In contrast, in a 2003 study of US physicians, the non concierge-based average panel size was 2,300 patients.^3^

Determining the right or optimal panel size for a full-time physician and team is a complex undertaking, balancing the demands of the system (patient access to care, clinical effectiveness or quality, patient experience, and cost) with the needs of the provider team (physician/team satisfaction, adequate time for care, and avoidance of physician/team burnout).

The standard method for determining panel size has been a function of multiplying a provider’s available slots each day by the number of days in clinic divided by the average number of visits each patient will make each year. But this method does not account for the tasks that occur outside of traditional face-to-face clinical visit, including patient communication (letter writing, telephone calls, emails, and form completion), test follow-up, panel management activities, and care coordination.

The VA’s patient population tends to be older and sicker than the average patient panel in other systems. Veterans have a higher disease burden, including a higher prevalence of diabetes mellitus, obesity, hypertension, and depression. Patients with a higher disease burden and larger list of prescriptions will likely be higher utilizers, placing heavier higher demand on their care teams.

## Determining the Right Size Panel

The importance of the primary care physician (PCP) is well documented. Starfield and colleagues note “six mechanisms, alone and in combination, may account for the beneficial impact of primary care on population health. They are (1) greater access to needed services, (2) better quality of care, (3) a greater focus on prevention, (4) early management of health problems, (5) the cumulative effect of the main primary care delivery characteristics, and (6) the role of primary care in reducing unnecessary and potentially harmful specialist care.” At the heart of primary care is the primary care provider and panel of patients that he or she cares for (often with the help of a team).^4^

In order for this pairing to be successful, patients need access to their primary care provider, which manifests as a timely appointment – to be seen when they want to be seen. Having an open slot day-of is the gold standard, but many systems have also implemented secure messaging, e-visits, and telemedicine to improve access for patients.

More than any other provider group, primary care providers are highly evaluated on a number of quality of care measures. The Healthcare Effectiveness Data and Information Set performance measures and admission rates for ambulatory care sensitive conditions are either fully or partially attributed to PCPs. Some systems use these measures to calculate salary components. The effect of panel size on these performance metrics is one of the subjects of this review.

Ultimately, PCPs want to provide high-quality, comprehensive care to their panel of patients. The difficulty in determining the right size panel, to ensure that providers have the time to do all their tasks, is a problem that has yet to be solved. External factors like physician shortages contribute to the problem when systems suggest that panel sizes need to be increased to cover more patients in the face of inadequate numbers of PCPs. Such processes will undoubtedly contribute to burnout by not allowing providers sufficient time to perform all of their required tasks.

In the era of big data and the electronic health record it is possible to start the process of determining the right size panel by calculating the complexity and demand of the patient population that the provider is caring for. Current workload could be monitored in real time and adjustments could be made as to the closing or opening of a panel to new patients. Additional inputs into these determinations include access parameters like the third next available appointment, patient waiting times, perceived access, and patient satisfaction. Quality metrics could be monitored to provide feedback to providers and determine if providers have adequate time for population management. The final input could be continuous monitoring of provider satisfaction and emotional stress in to order to intervene early to prevent provider burnout. Preventing provider burnout has implications on recruitment and retention of the next generation of primary care providers.