# Executive Summary

## Introduction

In 2009, the Veterans Health Administration Handbook 1101.02 established a baseline panel size of 1,200 patients for a full-time physician in a Patient Aligned Care Team (PACT). This number could be adjusted up or down based on availability of support staff, the number of examination rooms, and patient complexity. After adjustment for these factors, panels ranged from 1,000 to 1,400. Veterans Health Administration (VHA) Directive 1406 reaffirmed both the baseline panel numbers and adjustment parameters.

Determining the right or optimal panel size for a full-time physician and team is a complex undertaking, balancing the demands of the system (patient access to care, clinical effectiveness or quality, patient experience, and cost) with the needs of the provider team (physician/team satisfaction, adequate time for care, and avoidance of physician/team burnout).

The standard method for determining panel size has been a function of multiplying a provider’s available slots each day by the number of days in clinic divided by the average number of visits each patient will make each year. But this method does not account for the tasks that occur outside of traditional face-to-face clinical visit, including patient communication (letter writing, telephone calls, emails, and form completion), test follow-up, panel management activities, and care coordination.

To help inform an expert panel that will consider issues about determining VA primary care panel size, we were asked to conduct a systematic review of the literature.

## Methods

This topic was developed in response to a nomination by Karin Nelson, Director of the Office of Primary Care’s Analytics Team (PCAT) and Primary Care Physician. Key questions were then developed with input from the topic nominator, the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

The Key Questions were:

- KQ1A. How should panel size be determined for a primary care provider?
- KQ1B. What is the optimal size of a patient panel in primary care?
- KQ1C. Is there evidence to suggest that MDs, NPs, and PAs should have different panel sizes?
- KQ1D. Is there evidence from large health systems in terms of setting and maintaining panel sizes?
- KQ2. Should primary care panel sizes be risk-adjusted for patient complexity? If yes, how should risk adjustment be accomplished?

### Data Sources and Searches

We conducted searches in PubMed from inception to 03/08/2019, Web of Science from inception to 03/10/2019, and Scopus and Embase from inception to 03/08/2019. We also searched the gray literature using Google.

### Study Selection

There was no restriction on study design, but publications must have presented research with original data that tested a hypothesis (eg, the association between panel size and an outcome of interest) or with the description of a model to calculate panel size, or be a toolkit to help determine panel size.

### Data Abstraction and Quality Assessment

We abstracted data on the following: practitioner type, study design, sample size (number of practices), panel size range, other factors, and outcomes of interest. We considered outcomes of interest to be the 6 Institute of Medicine (IOM) aims for health care improvement (safe, effective, patient-centered, timely, efficient, equitable) and added to this the aim of reducing provider burnout.

### Data Synthesis and Analysis

We did not use quality assessment per se, because all but 1 of the included hypothesis-testing studies were observational and cross-sectional in design, which have limited ability to support causal inferences and are therefore considered to be low-quality evidence. The remaining studies are modeling studies, for which there is no generally accepted tool for assessing quality. However, we narratively discuss the strengths and limitations of the models in addition to their findings. The observational studies were too clinically heterogeneous to support meta-analysis; hence our synthesis is narrative. We used criteria similar to those proposed by the Grading of Recommendations Assessment, Development and Evaluation (GRADE) working group to assess the certainty of evidence.

## Results

### Results of Literature Search

We identified 448 potentially relevant citations, and 14 additional articles from reference-mining the included studies, for a total of 462 articles whose titles were screened. A total of 30 publications were identified at full-text review as meeting initial inclusion criteria. This included 16 hypothesis-testing studies that assessed the association of panel size with an outcome of interest, 11 studies of models, and 3 toolkits.

### Summary of Results for Key Questions

#### Key Question 1A How should panel size be determined for a primary care provider?

“How should…” is a question for policymakers that requires value judgments that balance multiple factors, and as such is not something that can be answered by an evidence review. In the remaining sections we describe the evidence policymakers can use when making judgments about how should panel size be determined.

#### Key Question 1B What is the optimal size of a patient panel in primary care?

Questions about optimization require that an outcome be chosen to be optimized. Since the important outcome may differ among stakeholders, we included in this section the evidence of the association of panel size with the 6 IOM aims of health care, plus the aim of reducing provider burnout.

There is a modest literature of observational studies, all but 1 being cross-sectional, that assess the relationship between panel size and outcomes of interest. The greatest number of studies assess the IOM aim of timely care, either as access or continuity. In general, these studies found variable access results, some reporting better access, others reporting worse access. Continuity seems to be little affected. There were fewer studies assessing the association between panel size and clinical quality and between panel size and patient experience (3 studies each). In general, these studies showed negative statistically significant relationships of modest size, or no statistically significant relationship, between increasing panel size and various measures of clinical quality and patient experience. One study reported 1 clinical quality measure that had better performance associated with increased panel size. No study assessed the relationship between panel size and cost. One study found a cross-sectional relationship between increased panel size and physician burnout. We did not identify any studies assessing the association of panel size and patient safety or equity.

We identified 4 groups of studies that built and assessed models for determining panel size. The modeling studies have varied in how they used or estimated important variables, such as predictors of patient demand, the source of the estimates for those predictors of demand, whether the demand is stochastic or not, and the optimization technique used. All models are optimizing some measure of access or continuity, and have either explicitly or implicitly assumed that other aims for health care improvement, such as clinical quality or patient experience, are equivalent with changes in panel size. A consistent finding from the modeling studies is that the optimal panel size for measures of access changes when patient factors are considered.

#### Key Question 1C Is there evidence to suggest that MDs, NPs, and PAs should have different panel sizes?

We found no empirical evidence to inform this question in the published or gray literature.

#### Key Question 1D Is there evidence from large health systems in terms of setting and maintaining panel sizes?

We identified no evidence per se on this topic. We identified only 2 US-based studies and 1 study from the English National Health Service, but none of these discussed how panel sizes are set or maintained.

#### Key Question 2 Should primary care panel sizes be risk-adjusted for patient complexity? If yes, how should risk adjustment be accomplished?

A consistent finding of the modeling studies is that the optimal panel size for measures of access is sensitive to risk adjustment for patient complexity. Which method of adjustment – which has varied from a simple method that includes age, gender, and insurance status to a complex method that includes many patient health status and prior utilization variables collected from the electronic health record – is “better” has not been tested in head-to-head comparisons, other than to conclude that even the simple method is an improvement over a method that considers just age and gender.

## Discussion

### Key Findings and Strength of Evidence

The evidence about the effect of panel size on the Institute of Medicine aims for health care improvement is surprisingly thin, given the importance of primary care panel size to all models of population-based care. The evidence consists of a handful of cross-sectional studies that assess associations of panel size with clinical quality, patient experience, access, and continuity, and show variable, no, or negative associations of increasing panel size on these outcomes of interest. By their design these studies cannot support conclusions about increasing panel size being the cause of any differences in outcomes. These studies at best act as a signal that there might be causal relationships between larger panel size and worse clinical quality and worse patient experience. The remainder of the evidence consists of a handful of studies that try and model what should be an optimal panel size, where “optimal” is defined exclusively by access. The modeling studies make the assumption that every additional patient added to a panel is going to be delivered with equal quality and patient-centeredness regardless of the number added. The cross-sectional studies we identified provide a signal that this assumption may not be correct. What does seem clear from the modeling studies is that simple models developed years ago, which basically take the number of visits made by existing patients and the number of appointment slots available to determine the panel size, can be improved. Not all patients require the same amount of time, and risk-adjusting methods tested vary from simple (age and gender) to complex (number of health care conditions, number of medications, and more). Furthermore, the resources available to the primary care provider influence how many patients can be cared for, as well as resources like the number of rooms available to see patients, the ability to delegate tasks to advanced practice providers, and the availability of clinical staff such as RN managers. Lastly, since the early models were developed there has been a plethora of new developments in health care that will influence how many patients can be cared for, such as the rise of non-face-to-face visits, telehealth, and the use of secure messaging, along with a much greater load of information the primary care provider needs to process, and be accountable for.

Certainty of Evidence for the Effect of Panel Size on Aims of Healthcare

Outcome | Number of studies | Study limitations | Consistency | Direction of effect | Overall Certainty of Evidence
Safe | 0 | N/A | N/A | N/A | Very Low
Effective (Clinical quality) | 3 | Serious | Mostly consistent | No association or negative association of modest size | Low
Patient centered | 3 | Serious | Inconsistent | No association or negative associations of modest size | Low
Timely (Access, including Continuity) | 8 | Serious | Inconsistent | Variable | Low
Efficient (including Cost) | 0 | N/A | N/A | N/A | Very Low
Equitable | 0 | N/A | N/A | N/A | Very Low
Provider burnout | 1 | Serious | N/A | Increased physician burnout with panel sizes higher than 1,200 | Very Low

Certainty of Evidence for Risk-adjustment

Outcome | Number of studies | Study limitations | Consistency | Direction of effect | Overall Certainty of Evidence
Access | 5 | Not serious | Consistent | Better optimization when panel sizes are adjusted for case mix | Moderate
Access | 2 | Not serious | Consistent | Risk adjustment that includes clinical conditions is better than risk adjustment with just age and sex in optimizing access | Moderate

### Applicability

Four of the studies identified were done in VA populations and therefore are directly relevant to VA. However, even these studies use VA data that are 5–10 years old. Primary care delivery in VA has been changing rapidly (for example, PACT), suggesting that the results of these VA studies may already be out of date.

### Research Gaps/Future Research

A substantial amount of research is needed before declarations of what constitutes an “optimal” panel size in primary care can claim to be evidence-based. These needs include VA-based studies of associations – longitudinal if possible, cross-sectional if necessary – of differences in panel size and IOM aims other than access, plus provider burnout. Existing VA data in Strategic Analytics for Improvement and Learning (SAIL) and Patient Centered Management Module (PCMM) could be leveraged for this. Even better, causal evidence could come from experimental changes in panel size on clinical quality, access, patient experience, etcetera, and burnout. This would involve intentional changes in panel size – say an increase or decrease by 20% – being applied to existing primary care physician (PCP) panels, and then a comparison being made of outcomes to practitioners whose panel sizes remained unchanged. A third line of research could focus on risk adjustment. VA patients tend to be more complex than non-VA patients, but the variation in complexity has been less well-studied.

More fundamentally, evidence is needed about the appropriate visit frequency or follow-up time, and format (face-to-face, video or telephone, or secure messaging), for patients with chronic conditions. Most currently used visit frequencies or follow-up times (such as a visit frequency of twice a year for a patient with well-controlled diabetes and hypertension) are based on historical norms, are variable between physicians, and lack evidence that the particular frequency produces better outcomes than some other frequency. Thus, panel size calculations that take a provider’s current patients and uses their prior year’s number of visits in order to calculate what size panel the provider can care for simply perpetuate historical provider-specific variability in visit frequency. Having evidence that a particular frequency produces better outcomes will help break through this endogenous reasoning.

### Conclusions

The evidence about the effect of panel size on the IOM aims for health care improvement is thin. The few studies available provide a signal that increasing panel size may have an association with modest worsening of clinical quality and patient experience. Several modeling studies exist, but all model only the effect of panel size on access to care, and assume that other IOM aims are constant with increasing panel size. Modeling studies support the policy that risk-adjustment and practice-level variables influence the optimal panel size for access. Current recommendations regarding primary care panel size are based more on historical experience than on evidence.

## Abbreviations Table

CPRS: Computerized Patient Record System
ESP: Evidence Synthesis Program
GRADE: Grading of Recommendations Assessment, Development and Evaluation
HCC: Hierarchical Conditions Categories
IOM: Institute of Medicine
MGMA: Medical Group Management Association
PACT: Patient Aligned Care Team
PCMM: Patient Centered Management Module
PCP: Primary Care Physician
RVU: Relative Value Unit
SAIL: Strategic Analytics for Improvement and Learning
SF-12: 12-Item Short Form Health Survey
SHEP: Survey of Healthcare Experiences of Patients
TEP: Technical Expert Panel
TNAA: Third Next Available Appointment
UPC: Usual Provider Continuity Index
VHA: Veterans Health Administration