# APPENDIX C Citations for Excluded Studies

## Background (n=15)

1 Panel size expansion in the medical home. 2010.
2 Patient Centered Management Module (PCMM) for Primary Care. 2017.
3 Facilitating Panel Management. 2018.
4 Bavafa H, Hitt LM, Terwiesch C. The Impact of E-Visits on Visit Frequencies and Patient Health: Evidence from Primary Care. Manage Sci. 2018;64(12):5461–5480.
5 Chamblee J, S R. Using patient panel as a principle element in primary care physician compensation. 2018.
6 Chien AT, Kyle MA, Peters AS, . The degree to which practice configuration, size, and composition change while practices establish Teams. Journal of general internal medicine. 2017;32(2):S335.
7 Chung S, Eaton LJ, Luft HS. Standardizing primary care physician panels: is age and sex good enough?. The American journal of managed care. 2012;18(7):e262–268.22823555
8 Edwards ST, Marino M, Balasubramanian BA, . Burnout Among Physicians, Advanced Practice Clinicians and Staff in Smaller Primary Care Practices. Journal of general internal medicine. 2018;33(12):2138–2146.30276654
9 Huang PY, Yano EM, Lee ML, Chang BL, Rubenstein LV. Variations in nurse practitioner use in Veterans Affairs primary care practices. Health services research. 2004;39(4 Pt 1):887–904.15230933
10 Hulshof P, Vanberkel, PT, Boucherie, RJ, Hans, EW, van Houdenhoven, M, van Ommeren, JKC Analytical models to determine room requirements in outpatient clinics. OR Spectrum. 2012;34(2):391–405.
11 Improvement IoH. Manage Panel Size and Scope of Practice.
12 Kivlahan C, C S. Identifying the Optimal Panel Sizes for Primary Care Physicians. 2018.
13 Kivlahan C, Pellegrino K, Grumbach K, . Calculating primary care panel size. 2017.
14 S S. How many patients can a primary care physician care for? 2014.
15 Virani SS, Akeroyd JM, Ramsey DJ, . Health Care Resource Utilization for Outpatient Cardiovascular Disease and Diabetes Care Delivery Among Advanced Practice Providers and Physician Providers in Primary Care. Popul Health Manag. 2018;21(3):209–216.28994631

## Duplicate (n=2)

1 Balasubramanian H, Denton B, M L. Managing physician panels in primary care. In. Handbook of healthcare delivery systems 2011.
2 Mayo-Smith MF, Frisbee K, Harvey C, Stefos T, Burgess J, Miller M. Relationship of primary care panel size and healthcare outcomes in the VA. Journal of general internal medicine. 2006;21:123–123.16336619

## Non-Systematic Review (n=1)

1 Ahmadi-Javid A, Jalali Z, Klassen KJ. Outpatient appointment systems in healthcare: A review of optimization studies. Eur J Oper Res. 2017;258(1):3–34.

## Not about Panel Size (n=9)

1 Cheung A, Stukel TA, Alter DA, . Primary Care Physician Volume and Quality of Diabetes Care A Population-Based Cohort Study. Ann Intern Med. 2017;166(4):240-+.27951589
2 Devlin RA, Hogg W, Zhong JW, Shortt M, Dahrouge S, Russell G. Practice size, financial sharing and quality of care. BMC Health Serv Res. 2013;13.
3 Ellis R, Ash A, J F. “Good-Enough” Risk Adjustment Models for Physician Payment and Performance Assessment. In:2015.
4 Huntley A, Lasserson D, Wye L, . Which features of primary care affect unscheduled secondary care use? A systematic review. BMJ Open. 2014;4(5):e004746.
5 Liu N, S Z. Panel size and overbooking decisions for appointment-based services under patient no-shows. Prod Oper Manag. 2014;23(12):2209–2223.
6 Marx R, Drennan MJ, Johnson EC, Hirozawa AM, Tse WM, Katz MH. Assessing and increasing patient panel size in the public sector. Journal of public health management and practice : JPHMP. 2011;17(6):506–512.21964361
7 Stempniewicz R, J C. Primary care panel size: Exploratory Analysis. 2015.
8 Wang JS, Lin SY, Sheu WH, Lee IT, Tseng LN, Song YM. Effects of patient volume on quality of outpatient diabetes care. Diabetes Res Clin Pract. 2009;84(2):e27–29.19269708
9 Zantingea EM VP, de Bakkera DH. The workload of general practitioners does not affect their awareness of patients’ psychological problems. Pat Educ Counsel. 2007;67:93–99.

## Unavailable (n=1)

1 Danforth KN, Slezak JM, Chen LH, . Risk factors for care-gaps in abnormal lab results follow-up within a large integrated health system. Diagnosis. 2017;4(4):eA118–eA119.

## Commentary (n=1)

1 Keller AO. Does team-based task delegation affect patient panel size for primary care providers? JAAPA-J Am Acad Physician Assist. 2015;28(6).

## Not a Predictor (n=1)

1 Chien AT, Kyle MA, Peters AS, . Establishing Teams How Does It Change Practice Configuration, Size, and Composition? J Ambul Care Manag. 2018;41(2):146–155.