# APPENDIX B Peer Review Comments/Author Responses

Question | Reviewer comment | Authors’ response
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | Yes - Helfrich CD, Simonetti J, Clinton WL, Wood GB, Taylor L, Schectman G, Stark R, Fihn SD, Nelson KM*. The Association of Team-Specific Workload and Staffing with Odds of Burnout Among VA Primary Care Team Members. 2017; J Gen Intern Med. 32 (7): 760–766.28233221 28233221; Has information on staffing, panel size overcapacity and burnout. | Thank you for this! We have now included this study in our analysis.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | Yes - Hannah Neprash did her dissertation on a related area. See http://scholar.harvard.edu/files/hannahneprash/files/neprash_jmp_november2016.pdf; Hannah is now an assistant professor at UMN.; https://directory.sph.umn.edu/bio/sph-a-z/hannah-neprash | This is an interesting dissertation, but it does not relate directly to panel size. We therefore did not add it to our review. However, Dr. Neprash is an expert in this area, and we will bring to the Coordinating Center the suggestion to contact her.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | See comments and corrections inserted in document attached. | Thank you for these comments and corrections. They are now addressed in-text.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Page 8 “The emergence of the 1,200 patient panel is somewhat of a mystery” could be changed to “The emergence of the 1,200 patient panel size was based on historical means at the time”; Page 17 “this study is of marginal relevance to VA non-teaching clinic care” could include the point that it would be relevant to teaching clinics panel sizes. | Thank you for these comments! We have now made these changes to the text.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | This is fairly comprehensive review of the primary care panel size question across clinical, health services and operations research literature. It is well written; it is not a mere summary, but advances empirically grounded judgments on the existing literature and what is missing. I am not aware of any important studies that have been omitted. The conclusions are sound and correctly point out that causal relationships between panel size and key outcomes such as clinical quality, patient experience, access and continuity have not yet been measured. In fact, this is a massive gap in the literature and it exists because techniques such as randomized control trials and longitudinal studies are are probably difficult to implement in the primary care setting. The authors correctly state that risk adjustment is key while considering panel size, as is the increasingly dominant role of non face to face work. The section on future research offers promise that the gaps in the literature could be addressed through research at VA. | Thank you for your comments!
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | The goal of this report is to review the scientific evidence behind primary care providers panel metrics. These metrics are used for a variety of functions from deciding when to hire more providers to creating bonuses (penalties) for high (low) performing providers. The reviewers combed through the literature finding 462 potential articles. Most articles were excluded upon further review and the final sample included 29, as shown in figure 1. Typically most syntheses grade the quality of the evidence or weight the meta-analytic results with the sample size. The authors acknowledge that this was not done here as all of the articles were observational or modeling exercises. I offer some comments and below:; 1. The authors do a nice job explaining the rationale for panel size and the adoption of panel metrics in VA. The authors might want to explain that panel metrics in commercial health care plans may be measuring a different denominator than VA panels. In commercial plans, a patient can only have 1 primary insurer. That is not the case in the VA. Because VA coverage is an entitlement, not a benefit, a Veteran can be in a commercial plan and also have a primary care provider in VA. In fact, most older Veterans are enrolled in Medicare with a substantial number in Medicare Advantage. When dually covered, the Veterans can choose to use the VA or non-VA providers. This has implications for panel management in VA that is rarely discussed. But it is worth noting that the underlying denominator may be different.; 2. On page 15, the authors review some existing papers and generally note that higher panel sizes were associated with worse outcomes (effectiveness). If possible, I would encourage the authors to report marginal effects. The odd ratios are not that informative. In addition, readers need to understand if there are thresholds as well as the levels of uncertainty. They do a little of this on the study from Ottawa, but greater details here would be very helpful. Possibly a table of these outcomes would be helpful.; 3. Page 17, the authors review 1 study that measured efficiency. It should be noted that charges is not a good measure of costs or efficiency. There is good reason to argue that this study should be ignored and that this area hasn’t been studied well at all.; 4. I would encourage the authors to connect with Hannah Neprash, if they haven’t done so yet. She did her dissertation on this issue and has evaluated a natural experiment that might provide causal estimates. She is now an assistant professor at Minnesota.; In summary, the authors do a very good job reviewing the literature. The lack of evidence on this topic is rather shocking given how these metrics are used for management. | 1. Great point. We now address dual eligibility in the Applicability to the VA section in the Discussion on pg. 31.; 2. Thank you for this comment. We have now added the marginal effects in text for the Stefos and Dahrouge (Ottawa) papers. Angstman and colleauges did not provide enough data to calculate marginal effects.; 3. We now note that charges are not a good measure of costs or efficiency in the Results.; 4. We will bring to the Coordinating Center the suggestion to contact Dr. Neprash for her expertise on the subject.; Thank you for your comments!