# APPENDIX A Search Strategies

DATABASE SEARCHED & TIME PERIOD COVERED:

PubMed - From inception to 3/8/2019

LANGUAGE:

English

SEARCH STRATEGY:

"panel size"

=====================================================================

DATABASE SEARCHED & TIME PERIOD COVERED:

WEB OF SCIENCE Indexes=SCI-EXPANDED, SSCI, A&HCI, CPCI-S, CPCI-SSH, BKCI-S, BKCI-SSH, ESCI, CCR-EXPANDED, IC – From inception to 3/10/2019

LANGUAGE:

English

SEARCH STRATEGY #1:

"panel size"

Refined by: WEB OF SCIENCE CATEGORIES: ( MEDICINE GENERAL INTERNAL OR HEALTH CARE SCIENCES SERVICES OR PRIMARY HEALTH CARE OR HEALTH POLICY SERVICES OR MEDICAL INFORMATICS OR PEDIATRICS OR ENGINEERING BIOMEDICAL OR GERIATRICS GERONTOLOGY OR GERONTOLOGY OR INFECTIOUS DISEASES OR MEDICINE RESEARCH EXPERIMENTAL )

SEARCH STRATEGY #2:

Cited searches on the following articles:

1. 2017. Hausmann, L. R. M., A. Canamucio, S. Gao, A. L. Jones, S. Keddem, J. A. Long and R. Werner. “Racial and Ethnic Minority Concentration in Veterans Affairs Facilities and Delivery of Patient-Centered Primary Care.” Popul Health Manag 20(3): 189–198.27575978
2. 2016. Rajkomar, A., J. W. Yim, K. Grumbach and A. Parekh. “Weighting Primary Care Patient Panel Size: A Novel Electronic Health Record-Derived Measure Using Machine Learning.” JMIR Med Inform 4(4): e29.27742603
3. 2016. Hirozawa, A. M., M. E. Montez-Rath, E. C. Johnson, S. A. Solnit, M. J. Drennan, M. H. Katz and R. Marx. “Multivariate Risk Adjustment of Primary Care Patient Panels in a Public Health Setting: A Comparison of Statistical Models.” J Ambul Care Manage 39(4): 333–42.27576054
4. 2016. Dahrouge, S., W. Hogg, J. Younger, E. Muggah, G. Russell and R. H. Glazier. “Primary Care Physician Panel Size and Quality of Care: A Population-Based Study in Ontario, Canada.” Ann Fam Med 14(1): 26–33.26755780
5. 2016. Angstman, K. B., J. L. Horn, M. E. Bernard, M. M. Kresin, E. W. Klavetter, J. Maxson, F. B. Willis, M. L. Grover, M. J. Bryan and T. D. Thacher. “Family Medicine Panel Size with Care Teams: Impact on Quality.” J Am Board Fam Med 29(4): 444–51.27390375
6. 2013. Weiss, J. M., M. A. Smith, P. J. Pickhardt, S. A. Kraft, G. E. Flood, D. H. Kim, E. Strutz and P. R. Pfau. “Predictors of colorectal cancer screening variation among primary-care providers and clinics.” Am J Gastroenterol 108(7): 1159–67.23670114
7. 2013. Ozen, A. and H. Balasubramanian. “The impact of case mix on timely access to appointments in a primary care group practice.” Health Care Manag Sci 16(2): 101–18.23076360
8. 2012. Mohr, D. C. and G. J. Young. “Slack resources and quality of primary care.” Med Care 50(3): 203–9.22193414
9. 2012. Dahrouge, S., W. E. Hogg, G. Russell, M. Tuna, R. Geneau, L. K. Muldoon, E. Kristjansson and J. Fletcher. “Impact of remuneration and organizational factors on completing preventive manoeuvres in primary care practices.” Cmaj 184(2): E135–43.22143227
10. 2011. Stefos, T., J. F. Burgess, Jr., M. F. Mayo-Smith, K. L. Frisbee, H. B. Harvey, L. Lehner, S. Lo and E. Moran. “The effect of physician panel size on health care outcomes.” Health Serv Manage Res 24(2): 96–105.21471580
11. 2010. Balasubramanian, H., R. Banerjee, B. Denton, J. Naessens and J. Stahl. “Improving clinical access and continuity through physician panel redesign.” J Gen Intern Med 25(10): 1109–15.20549379
12. 2009. Hogg, W., S. Dahrouge, G. Russell, M. Tuna, R. Geneau, L. Muldoon, E. Kristjansson and S. Johnston. “Health promotion activity in primary care: performance of models and associated factors.” Open Med 3(3): e165–73.21603049
13. 2009. Francis, M. D., W. E. Zahnd, A. Varney, S. L. Scaife and M. L. Francis. “Effect of number of clinics and panel size on patient continuity for medical residents.” J Grad Med Educ 1(2): 310–5.21975997
14. 2008. Dobscha, S. K., K. Corson, J. A. Flores, E. C. Tansill and M. S. Gerrity. “Veterans affairs primary care clinicians’ attitudes toward chronic pain and correlates of opioid prescribing rates.” Pain Med 9(5): 564–71.18777608
15. 2007. Green, L. V., S. Savin and M. Murray. “Providing timely access to care: what is the right patient panel size?” Jt Comm J Qual Patient Saf 33(4): 211–8.17441559

DATABASE SEARCHED & TIME PERIOD COVERED:

Scopus – inception-3/8/2019

LANGUAGE:

English

SEARCH STRATEGY #1:

TITLE-ABS-KEY ("panel size")

AND

LIMIT-TO ( SUBJAREA , “MEDI” ) OR LIMIT-TO ( SUBJAREA , “SOCI” )

AND

EXCLUDE ( SUBJAREA , “BIOC” ) OR EXCLUDE ( SUBJAREA , “ENGI” ) OR EXCLUDE ( SUBJAREA , “AGRI” ) OR EXCLUDE ( SUBJAREA , “COMP” ) OR EXCLUDE ( SUBJAREA , “ARTS” )

STRATEGY #2:

Scopus – inception-3/10/2019

Cited searches on the above-listed 15 articles

=====================================================================

DATABASE SEARCHED & TIME PERIOD COVERED:

Embase – inception-3/8/2019

LANGUAGE:

English

SEARCH STRATEGY:

‘panel size’

AND

‘primary care’