# REFERENCES

1 Fawzy A, Wu TD, Wang K, . Racial and ethnic discrepancy in pulse oximetry and delayed identification of treatment eligibility among patients with COVID-19. JAMA Internal Medicine. 2022;182(7):730–738. doi:10.1001/jamainternmed.2022.1906 35639368
2 Henry NR, Hanson AC, Schulte PJ, . Disparities in hypoxemia detection by pulse oximetry across self-identified racial groups and associations with clinical outcomes. Critical Care Medicine. 2022;50(2):204–211. doi:10.1097/CCM.0000000000005394 35100193
3 Bangash MN, Hodson J, Evison F, . Impact of ethnicity on the accuracy of measurements of oxygen saturations: A retrospective observational cohort study. EClinicalMedicine. 2022;48:101428. doi:10.1016/j.eclinm.2022.101428 35706489
4 Burnett GW, Stannard B, Wax DB, . Self-reported race/ethnicity and intraoperative occult hypoxemia: A retrospective cohort study. Anesthesiology. 2022;136(5):688–696. doi:10.1097/ALN.0000000000004153 35231085
5 US Food and Drug Administration. Pulse oximeters − Premarket notification submissions: Guidance for industry and Food and Drug Administration staff. 2013. https://www.fda.gov/media/72470/download
6 Shi C, Goodall M, Dumville J, . The accuracy of pulse oximetry in measuring oxygen saturation by levels of skin pigmentation: A systematic review and meta-analysis. BMC Medicine. 2022;20(1):267. doi:10.1186/s12916-022-02452-8 35971142
7 Sjoding MW, Dickson RP, Iwashyna TJ, Gay SE, Valley TS. Racial bias in pulse oximetry measurement. New England Journal of Medicine. 2020;383(25):2477–2478. doi:10.1056/NEJMc2029240 33326721
8 U.S. Food and Drug Administration. Pulse oximeter accuracy and limitations: FDA safety communication. 2022. https://www.fda.gov/medical-devices/safety-communications/pulse-oximeter-accuracy-and-limitations-fda-safety-communication
9 Whiting P, Savovic J, Higgins JP, . ROBIS: A new tool to assess risk of bias in systematic reviews was developed. J Clin Epidemiol. 2016;69:225–34. doi:10.1016/j.jclinepi.2015.06.005 26092286
10 Whiting PF, Rutjes AWS, Westwood ME, . QUADAS-2: A revised tool for the quality assessment of diagnostic accuracy studies. Annals of Internal Medicine. 2011;155(8):529–536. doi:10.7326/0003-4819-155-8-201110180-00009 22007046
11 Hayden JA, van der Windt DA, Cartwright JL, Pierre Côté D, Bombardier C. Assessing bias in studies of prognostic factors. Annals of Internal Medicine. 2013;158(4):280–286. doi:10.7326/0003-4819-158-4-201302190-00009 23420236
12 Hoy D, Brooks P, Woolf A, . Assessing risk of bias in prevalence studies: Modification of an existing tool and evidence of interrater agreement. J Clin Epidemiol. 2012;65(9):934–9. doi:10.1016/j.jclinepi.2011.11.014 22742910
13 Tipton E, Shuster J. A framework for the meta-analysis of Bland–Altman studies based on a limits of agreement approach. Statistics in Medicine. 2017;36(23):3621–3635. doi:10.1002/sim.7352 28664537
14 Tang LL, Caudy M, Taxman F. A statistical method for synthesizing meta-analyses. Computational and Mathematical Methods in Medicine. 2013;doi:10.1155/2013/732989
15 Knapp G, Hartung J. Improved tests for a random effects meta-regression with a single covariate. Statistics in Medicine. 2003;22(17):2693–2710. doi:10.1002/sim.1482 12939780
16 Rover C, Knapp G, Friede T. Hartung-Knapp-Sidik-Jonkman approach and its modification for random-effects meta-analysis with few studies. BMC Med Res Methodol. 2015;15:99. doi:10.1186/s12874-015-0091-1 26573817
17 Parr NJ, Schweer-Collins ML, Darlington TM, Tanner-Smith EE. Meta-analytic approaches for examining complexity and heterogeneity in studies of adolescent development. J Adolesc. 2019;77:168–178. doi:10.1016/j.adolescence.2019.10.009 31739275
18 metafor: Meta-analysis package for R. Version 4.2-0. The Comprehensive R Archive Network; 2023. https://cran.r-project.org/web/packages/metafor/index.html
19 Ries AL, Farrow JT, Clausen JL. Accuracy of two ear oximeters at rest and during exercise in pulmonary patients. American Review of Respiratory Disease. 1985;132(3):685–9. doi:10.1164/arrd.1985.132.3.685 4037542
20 Gabrielczyk MR, Buist RJ. Pulse oximetry and postoperative hypothermia: An evaluation of the Nellcor N-100 in a cardiac surgical intensive care unit. Anaesthesia. 1988;43(5):402–404. doi:10.1111/j.1365-2044.1988.tb09025.x 3400853
21 Ries AL, Prewitt LM, Johnson JJ. Skin color and ear oximetry. Chest. 1989;96(2):287–90. doi:10.1378/chest.96.2.287 2752811
22 Escourrou PJ, Delaperche MF, Visseaux A. Reliability of pulse oximetry during exercise in pulmonary patients. Chest. 1990;97(3):635–8. doi:10.1378/chest.97.3.635 2106411
23 Jubran A, Tobin MJ. Reliability of pulse oximetry in titrating supplemental oxygen therapy in ventilator-dependent patients. Chest. 1990;97(6):1420–1425. doi:10.1378/chest.97.6.1420 2347228
24 Lee KH, Hui KP, Tan WC, Lim TK. Factors influencing pulse oximetry as compared to functional arterial saturation in multi-ethnic Singapore. Singapore Medical Journal. 1993;34(5):385–7.8153680
25 Bothma PA, Joynt GM, Lipman J, . Accuracy of pulse oximetry in pigmented patients. South African Medical Journal. 1996;86(5 Suppl):594–6.8914569
26 McGovern JP, Sasse SA, Stansbury DW, Causing LA, Light RW. Comparison of oxygen saturation by pulse oximetry and co-oximetry during exercise testing in patients with COPD. Chest. 1996;109(5):1151–1155. doi:10.1378/chest.109.5.1151 8625659
27 Adler JN, Hughes LA, Vivilecchia R, Camargo CA, Jr. Effect of skin pigmentation on pulse oximetry accuracy in the emergency department. Academic Emergency Medicine. 1998;5(10):965–70. doi:10.1111/j.1553-2712.1998.tb02772.x 9862586
28 Abrams GA, Sanders MK, Fallon MB. Utility of pulse oximetry in the detection of arterial hypoxemia in liver transplant candidates. Liver Transplantation. 2002;8(4):391–6. doi:10.1053/jlts.2002.32252 11965585
29 Hinkelbein J, Genzwuerker HV, Sogl R, Fiedler F. Effect of nail polish on oxygen saturation determined by pulse oximetry in critically ill patients. Resuscitation. 2007;72(1):82–91. doi:10.1016/j.resuscitation.2006.06.024 17098347
30 Hinkelbein J, Koehler H, Genzwuerker HV, Fiedler F. Artificial acrylic finger nails may alter pulse oximetry measurement. Resuscitation. 2007;74(1):75–82. doi:10.1016/j.resuscitation.2006.11.018 17353079
31 Muñoz X, Torres F, Sampol G, Rios J, Martí S, Escrich E. Accuracy and reliability of pulse oximetry at different arterial carbon dioxide pressure levels. Eur Respir J. 2008;32(4):1053–1059. doi:10.1183/09031936.00126507 18480106
32 Ebmeier SJ, Barker M, Bacon M, . A two centre observational study of simultaneous pulse oximetry and arterial oxygen saturation recordings in intensive care unit patients. Anaesthesia and Intensive Care. 2018;46(3):297–303. doi:10.1177/0310057x1804600307 29716488
33 Pilcher J, Ploen L, McKinstry S, . A multicentre prospective observational study comparing arterial blood gas values to those obtained by pulse oximeters used in adult patients attending Australian and New Zealand hospitals. BMC Pulmonary Medicine. 2020;20(1):7. doi:10.1186/s12890-019-1007-3 31918697
34 Harskamp RE, Bekker L, Himmelreich JCL, . Performance of popular pulse oximeters compared with simultaneous arterial oxygen saturation or clinical-grade pulse oximetry: A cross-sectional validation study in intensive care patients. BMJ Open Respiratory Research. 2021;8(1)doi:10.1136/bmjresp-2021-000939
35 Valbuena VSM, Barbaro RP, Claar D, . Racial bias in pulse oximetry measurement among patients about to undergo extracorporeal membrane oxygenation in 2019-2020: A retrospective cohort study. Chest. 2022;161(4):971–978. doi:10.1016/j.chest.2021.09.025 34592317
36 Wiles MD, El-Nayal A, Elton G, . Effect of patient ethnicity on the accuracy of peripheral pulse oximetry in patients with COVID-19 pneumonitis requiring mechanical ventilation. Anaesthesia. 2022;77(4):489–491. doi:10.1111/anae.15656 35001371
37 Cecil WT, Thorpe KJ, Fibuch EE, Tuohy GF. A clinical evaluation of the accuracy of the Nellcor N-100 and Ohmeda 3700 pulse oximeters. J Clin Monit. 1988;4(1):31–6. doi:10.1007/bf01618105 3339389
38 Wang YT, Poh SC. Noninvasive oximetry in pigmented patients. Annals of the Academy of Medicine, Singapore. 1985;14(3):427–9.4073807
39 Sudat SEK, Wesson P, Rhoads KF, . Racial disparities in pulse oximeter device inaccuracy and estimated clinical impact on COVID-19 treatment course. American Journal of Epidemiology. 2023;192(5):703–715. doi:10.1093/aje/kwac164 36173743
40 Valbuena VSM, Seelye S, Sjoding MW, . Racial bias and reproducibility in pulse oximetry among medical and surgical inpatients in general care in the Veterans Health Administration 2013-19: Multicenter, retrospective cohort study. BMJ. 2022;378:e069775. doi:10.1136/bmj-2021-069775 35793817
41 Blanchet M-A, Mercier G, Delobel A, . Accuracy of multiple pulse oximeter brands in stable critically ill patients - Oxygap study. Respiratory Care. 2023;doi:10.4187/respcare.10582
42 Crooks CJ, West J, Morling JR, . Differential pulse oximetry readings between ethnic groups and delayed transfer to intensive care units. QJM. 2023;116(1):63–67. doi:10.1093/qjmed/hcac218 36066450
43 Nguyen LS, Helias M, Raia L, . Impact of COVID-19 on the association between pulse oximetry and arterial oxygenation in patients with acute respiratory distress syndrome. Scientific Reports. 2022;12(1):1462. doi:10.1038/s41598-021-02634-z 35087122
44 Chesley CF, Lane-Fall MB, Panchanadam V, . Racial disparities in occult hypoxemia and clinically based mitigation strategies to apply in advance of technological advancements. Respiratory Care. 2022;67(12):1499–1507. doi:10.4187/respcare.09769 35679133
45 Seitz KP, Wang L, Casey JD, . Pulse oximetry and race in critically ill adults. Critical Care Explorations. 2022;4(9)doi:10.1097/CCE.0000000000000758
46 Wong A-KI, Charpignon M, Kim H, . Analysis of discrepancies between pulse oximetry and arterial oxygen saturation measurements by race and ethnicity and association with organ dysfunction and mortality. JAMA Network Open. 2021;4(11):e2131674–e2131674. doi:10.1001/jamanetworkopen.2021.31674 34730820
47 Jamali H, Castillo LT, Morgan CC, . Racial disparity in oxygen saturation measurements by pulse oximetry: Evidence and implications. Annals of the American Thoracic Society. 2022;19(12):1951–1964. doi:10.1513/AnnalsATS.202203-270CME 36166259
48 Braun L. Race correction and spirometry: Why history matters. Chest. 2021;159(4):1670–1675. doi:10.1016/j.chest.2020.10.046 33263290
49 Fawzy A, Valbuena VSM, Chesley CF, Wu TD, Iwashyna TJ. Dynamic errors in pulse oximetry preclude use of correction factor. Annals of the American Thoracic Society. 2022;20(2):338–339. doi:10.1513/AnnalsATS.202210-872LE
50 Vyas DA, Eisenstein LG, Jones DS. Hidden in plain sight — reconsidering the use of race correction in clinical algorithms. New England Journal of Medicine. 2020;383(9):874–882. doi:10.1056/NEJMms2004740 32853499
51 Okunlola OE, Lipnick MS, Batchelder PB, Bernstein M, Feiner JR, Bickler PE. Pulse oximeter performance, racial inequity, and the work ahead. Respiratory Care. 2022;67(2):252–257. doi:10.4187/respcare.09795 34772785
52 Sanjay GG, Vinoop D, Georgios A. Innovative technology to eliminate the racial bias in non-invasive, point-of-care (POC) haemoglobin and pulse oximetry measurements. BMJ Innovations. 2023;9(2):73. doi:10.1136/bmjinnov-2022-001018