# ACKNOWLEDGMENTS

The authors are grateful to Becky Baltich Nelson, MLS, MS, for literature searching, Payten Sonnen for editorial and citation management support, external peer reviewers, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- John W. Nord, MD, MSc
  Acting Deputy Chief Officer
  Veterans Health Administration (VHA) Office of Specialty Care Services

- Joseph Francis, MD, MPH
  Executive Director of Analytics and Performance Integration
  VHA

- Mel L. Anderson, MD, MACP
  Executive Director
  VHA National Hospital Medicine Program

- Thomas S. Valley, MD
  Research Scientist and Staff Physician
  Center for Clinical Management Research (VA Ann Arbor Healthcare System)

This report was prepared by the Evidence Synthesis Program Center located at the VA Portland Health Care System, directed by Mark Helfand, MD, MPH, MS, and funded by the Department of Veterans Affairs, Veterans Health Administration, Health Services Research and Development.

The findings and conclusions in this document are those of the author(s) who are responsible for its contents and do not necessarily represent the views of the Department of Veterans Affairs or the United States government. Therefore, no statement in this article should be construed as an official position of the Department of Veterans Affairs. The final research questions, methodology, and/or conclusions may not necessarily represent the views of contributing operational and content experts. No investigators have affiliations or financial involvement (eg, employment, consultancies, honoraria, stock ownership or options, expert testimony, grants or patents received or pending, or royalties) that conflict with material presented in the report.