# DISCUSSION

Based on a large body of evidence, pulse oximeters likely overestimate Black patients’ blood oxygen saturation level. Most available oximetry data is from recent studies conducted in contemporary hospital and health system settings and using modern pulse oximeters. In these studies, pulse oximeters also appear to have the largest bias and greatest imprecision among Black patients, though some degree of bias and considerable imprecision is evident regardless of patient race/ethnicity. Occult hypoxemia is likely more common among Black patients compared with White patients. Asian, Latino or Hispanic, Native American or Indigenous, or other or mixed race/ethnicity patients may also experience occult hypoxemia more frequently than White patients, but evidence in these groups is less certain. Studies examining differences in clinical outcomes associated with occult hypoxemia or biases in pulse oximeter accuracy are methodologically inconsistent but provide suggestive evidence that Black patients with undetected hypoxemia could experience poorer treatment delivery and clinical outcomes than White patients with undetected hypoxemia.

Re-assessing oxygen saturation in arterial blood more routinely—particularly for patients who show signs or symptoms of arterial hypoxemia—has been proposed as one step to reduce the risk of occult hypoxemia and subsequent harms arising from biases in pulse oximeter readings.^40^ Another approach suggested to mitigate this risk is to raise the oxygen saturation range from 92–96% to 94–98%, though this may increase risk of hyperoxemia.^44^ Applying a skin-tone-based correction factor to readings from currently available pulse oximeters has also been discussed,^47^ but such adjustments have a controversial history^48–50^ and may have limited efficacy because the accuracy and reliability of pulse oximetry readings is influenced by a number of factors that cannot be accounted for in a single correction factor.^47,49^ A broader recommendation has been to revise guidelines for pulse oximeter validation studies, in particular to require enrolling more patients with darker skin pigmentation, testing oximeters under real-world health care conditions, and incorporating perfusion into validation requirements.^44,51^

As noted earlier, the systematic review by Shi et al^6^ identified some studies that reported pulse oximeter accuracy by skin pigmentation level rather than race or ethnicity. We focused on the latter because most available accuracy data is from recent studies that report their results by race/ethnicity (likely due to the use of patient health record data). A concern with the use of race/ethnicity in accuracy studies is that it may introduce spurious variation across studies and lead to unexpected or clinically counterintuitive findings, given that individuals with a wide range of skin pigmentation levels may identify with the same race/ethnicity.

For instance, groups made up of patients identified as Black through health record data may, in one hypothetical study, be composed of individuals who on average have lighter skin pigmentation compared with a Black patient group in a different study. Variation in sample composition could be caused by many factors, including geographic or other contextual differences between the studies, or may simply be due to chance. In the former study, pulse oximeter bias in the Black patient group may be smaller and closer to levels observed among White patients, while in the latter study, bias in the Black patient group may be more substantial. Underlying differences in sample composition by skin pigmentation level, therefore, resulted in inconsistent evidence about the same race/ethnicity group. Moreover, findings from any single study (eg, the first study, in which bias was similar across groups) could be inappropriately generalized because they do not account for the composition of patient groups relative to skin pigmentation level. Given these considerations, use of objective skin pigmentation metrics when determining the accuracy of pulse oximeters has been proposed.^51^ Extending this recommendation to prospective research on disparities in occult hypoxemia is likely warranted.

Finally, it has been acknowledged that addressing biases in pulse oximeter readings and in the care that follows from those readings requires fundamental advancements in the technologies used for routine oxygen saturation monitoring. Fawzy et al^1^ state:

“Although increased awareness of the limitations of pulse oximetry may mitigate some of the adverse effects…the race and ethnicity-based discrepancy of pulse oximetry exposes a fundamental flaw in the acquisition rather than interpretation of data, although all the aforementioned biases are associated with systematic underdiagnosis of disease or withholding of therapies for racial and ethnic minority groups.”

Improving pulse oximeter technology is an active research area. A small validation study^52^ published earlier this year, for example, tested an investigational noninvasive oximeter that uses green rather than the conventional red light, is designed to target superficial skin layers to increase sensitivity to tissue hypoxia, and implements patient-specific skin tone calibration (rather than a pre-programmed correction factor). The study enrolled equal proportions of patients with fair skin, brown skin, and dark skin. Oxygen saturation readings from the novel oximeter were more highly correlated with blood-based oximetry (r = 0.76) than pulse oximeter readings (r = 0.47), and the novel oximeter was also able to accurately assess oxygen levels in cases in which the pulse oximeter failed, including a patient with very high skin pigmentation.

## Limitations

Incorporating an existing review of pulse oximeter accuracy meant that we could not exclude studies with limited relevance to modern clinical practice among Veterans (ie, studies that used older pulse oximeter technologies or pediatric samples). Observations from these studies make up a small proportion of available accuracy data, so it is unlikely this limitation impacts the validity of the review’s findings. We also used sequential data abstraction and risk of bias assessment rather than a fully independent (blinded) process.

## CONCLUSIONS

Pulse oximeters likely overestimate Black patients’ blood oxygen saturation level, increasing the risk for unrecognized or occult hypoxemia. Occult hypoxemia occurs to some degree in all races/ethnicities but is likely more common among Black patients compared with White patients. Findings of this review underscore that clinicians should be aware of the risk of occult hypoxemia in patients with darker skin pigmentation. Moreover, while pulse oximeter readings are on average fairly similar to arterial oxygen saturation levels, evidence from hospital and health system settings relevant to the VA suggests that the amount of bias could vary substantially from patient to patient regardless of their race/ethnicity. This finding implies that incorporating conventional race or ethnicity-based correction factors into pulse oximeters would not eliminate disparities in occult hypoxemia risk. Although proposed changes to clinical practice to accommodate bias and imprecision in pulse oximeters may help to mitigate harms in the near-term, advancements in noninvasive oximeter technology are needed. As the largest integrated health system in the United States, the VHA is uniquely positioned to cultivate innovations in oximeter technology.