# RESULTS

## LITERATURE FLOW DIAGRAM

The literature flow diagram summarizes the results of the study selection process. A full list of excluded studies is provided in the Appendix.

Notes. ^a^34 primary studies and 1 systematic review.

Abbreviations. CDSR=Cochrane Database of Systematic Reviews; CINAHL=Cumulative Index to Nursing and Allied Health Literature; SR=systematic review.

## OVERVIEW OF INCLUDED STUDIES

Our search identified 109 potentially relevant articles after deduplication and title and abstract screening. Of these, 34 primary studies and 1 existing systematic review and meta-analysis^6^ on pulse oximeter accuracy met eligibility criteria. Eighteen studies^19–36^ were included in the identified systematic review, which together provided 21,269 paired observations from 3,176 patients. These studies were published between 1985 and 2021 and varied considerably in setting and patient characteristics (details of all included studies are provided in the Appendix). We found 2 additional accuracy studies published in the 1980s^37,38^ but did not include these in formal syntheses because they used pulse oximeters that are no longer commercially available.

We located 4 recent observational studies^3,4,39,40^ that reported pulse oximeter accuracy data in sufficient detail for meta-analyses; together these studies contribute 241,680 new paired observations in 102,841 patients. Four other accuracy studies^36,41–43^ did not provide adequate outcome data or information about race/ethnicity groups to be included in formal syntheses. The 4 studies contributing accuracy data noted above also reported occult hypoxemia prevalence; in total, we included 11 observational studies^1–4,7,35,39,40,44–46^ that reported occult hypoxemia prevalence and 4 studies^1,2,39,46^ that examined the association between occult hypoxemia and clinical outcomes by patient race/ethnicity. Most newly identified studies used data from patients receiving acute care in academic or community hospitals or health systems. One study was limited to patients undergoing anesthesia^4^ and 2 studies included surgical inpatients.^2,40^ Patient race/ethnicity was generally self-reported.

## MAIN FINDINGS

### Pulse Oximeter Accuracy

Pooled mean bias and precision findings by race/ethnicity groups are shown in the Table below. In Black patients, pulse oximeters appear to overestimate blood oxygen saturation by an average of 1.5% compared with CO-oximetry in arterial blood (pooled mean bias = 1.54, 95% CI [0.99, 2.10]), based on 37,562 paired observations in 14,626 patients. Mean bias among Black patients was considerably larger than among White patients (0.62, 95% CI [−0.08, 1.32]; N_Obs_ = 154,286) or patients identifying as Asian, Latino or Hispanic, Native American or Indigenous, or other or mixed race/ethnicity (0.31, 95% CI [0.09, 0.54]; N_Obs_ = 71,101). Precision of pulse oximeter readings was comparable across race/ethnicity groups, with pooled SDs ranging from 1.61 to 1.98.^ii^ In recent studies that contribute most available oximetry data, mean bias was larger in all race/ethnicity groups compared with earlier evidence. The most substantial increase from older studies was among Asian, Latino or Hispanic, Native American or Indigenous, or other or mixed race/ethnicity patients (from 0.31% to 1.41%). Precision estimates were comparable across groups but considerably larger than in earlier studies (pooled SDs from 4.30 to 5.23), indicating greater variability in bias between patients.

The calculated A_RMS_ for all accuracy data was 1.64 for Black patients, 0.78 for White patients, and 0.75 for Asian, Latino or Hispanic, Native American or Indigenous, or other or mixed race/ethnicity patients. A_RMS_ values in newly identified studies were much larger: 2.57, 1.83, and 2.03, respectively.

Table Pulse Oximeter Accuracy, Occult Hypoxemia Prevalence, and Clinical Outcomes by Patient Race/Ethnicity

Patients Described as Black or African American
Accuracy | Patients | Paired Obs. | Mean Bias [95% CI] | Precision [95% CI]
Shi 2022 Review (k = 9) | 459 | 5,753 | 1.52 [0.95, 2.09] | 1.68 [1.32, 2.14]
Recent Studies (k = 4) | 14,167 | 31,809 | 1.96 [−0.57, 4.50] | 5.23 [1.50, 18.28]
Updated Estimate (k = 13) | 14,626 | 37,562 | 1.54 [0.99, 2.10] | 1.75 [1.38, 2.22]
Occult Hypoxemia Prevalence | | | % [95% CI] | [95% PI]
Patients (k = 5) | 34,869 | | 11.4 [4.6, 25.5] | [1.2, 58.1]
Paired Observations (k = 11) | | 76,177 | 6.9 [3.9, 11.9] | [0.9, 36.9]
Clinical Outcomes
Eligibility Recognition (k = 1) | 928 | | aHR: 0.71 [0.63, 0.80] (ref: White)
Treatment Delay (k = 1) | 681 | | Median (IQR): 7.0 h (1.9–20.8)
Length of Stay (k = 1) | 26,032 | | Difference: −3.0 d (p = .00)
In-hospital Mortality (k = 1) | 26,032 | | Difference: +5.9% (p < .001)
Patients Described as Asian, Latino or Hispanic, Native American or Indigenous, or Other
Accuracy | Patients | Paired Obs. | Mean Bias [95% CI] | Precision [95% CI]
Shi 2022 Review (k = 3) | 522 | 2,646 | 0.31 [0.09, 0.53] | 1.55 [0.53, 4.53]
Recent Studies (k = 3) | 23,001 | 68,455 | 1.41 [−2.65, 5.47] | 4.30 [0.63, 29.17]
Updated Estimate (k = 6) | 23,523 | 71,101 | 0.31 [0.09, 0.54] | 1.98 [0.78, 5.04]
Occult Hypoxemia Prevalence | | | % [95% CI] | [95% PI]
Patients (k = 5) | 25,130 | | 9.7 [3.2, 26.1] | [0.6, 66.6]
Paired Observations (k = 6) | | 89,243 | 5.3 [2.0, 13.0] | [0.4, 42.8]
Clinical Outcomes
Eligibility Recognition (k = 1) | Asian: 25; Hispanic: 445 | | aHR: 0.97 [0.62, 1.50]; 0.77 [0.66, 0.89] (ref: White)
Treatment Delay (k = 1) | Asian: 21; Hispanic: 323 | | Median (IQR): 7.7 h (3.5–13.6); 5.0 h (1.2–15.8)
Length of Stay (k = 1) | Asian: 1,919; Hispanic: 2,397 | | Difference: +0.5 d (p = .02); +0.8 d (p < .01)
In-hospital Mortality (k = 1) | Asian: 1,919; Hispanic: 2,397 | | Difference: +5.6% (p = .13); +4.6% (p = .06)
Patients Described as White or Caucasian
Accuracy | Patients | Paired Obs. | Mean Bias [95% CI] | Precision [95% CI]
Shi 2022 Review (k = 13) | 2,195 | 12,870 | 0.55 [−0.21, 1.31] | 1.55 [1.32, 1.83]
Recent Studies (k = 4) | 65,673 | 141,416 | 1.01 [−0.78, 2.79] | 4.63 [1.89, 11.37]
Updated Estimate (k = 17) | 67,868 | 154,286 | 0.62 [−0.08, 1.32] | 1.61 [1.37, 1.89]
Occult Hypoxemia Prevalence | | | % [95% CI] | [95% PI]
Patients (k = 5) | 109,286 | | 6.5 [2.8, 14.2] | [0.8, 36.8]
Paired Observations (k = 11) | | 337,976 | 3.3 [1.8, 5.9] | [0.4, 22.0]
Clinical Outcomes
Treatment Delay (k = 1) | 427 | | Median (IQR): 5.3 h (1.4–15.2)
Length of Stay (k = 1) | 57,623 | | Difference: −0.5 d (p < .01)
In-hospital Mortality (k = 1) | 57,623 | | Difference: +11.1% (p < .001)

Abbreviations. aHR=adjusted hazard ratio; CI=confidence interval; d=day; h=hour; IQR=interquartile range; k=number of studies; PI=prediction interval.

Although available studies of pulse oximeter accuracy generally use observational designs, we judged newly identified studies to be at moderate or low overall risk of biased findings. The most common concerns were unclear detail about the pulse oximeter or CO-oximeter devices used, lack of reporting on blinding (ie, whether pulse oximeter results were read without knowledge of SaO_2_), and limitations arising from use of health record data, including unclear detail about patient characteristics. Shi et al found that excluding studies with high risk of bias did not substantively alter conclusions. No newly identified studies included in syntheses were rated at high risk of bias.

Evidence on differential pulse oximeter accuracy by patient race/ethnicity from studies published prior to mid-2021 was rated as low or very low strength (certainty) by Shi et al. Despite pooled mean bias and SD values being larger in recent studies, the substantial increase in available data and consistent magnitude of findings led us to increase the strength of evidence supporting the finding that pulse oximeters overestimate SaO_2_ in Black patients to moderate. Although there were comparable increases in the amount of data available for other race/ethnicity groups, there was also much greater variability in paired readings. Given this, we did not upgrade the strength of evidence supporting the conclusion that pulse oximeters do not overestimate SaO_2_ to a clinically important degree among Asian, Latino or Hispanic, Native American or Indigenous, or other or mixed race/ethnicity patients (from low certainty). The same conclusion was upgraded to low strength or certainty (from very low certainty) for White patients because of the substantial increase in the number of observations contributing to pooled estimates.

### Occult Hypoxemia Prevalence

Occult hypoxemia prevalence by race/ethnicity groups is shown in the Table above. The pooled prevalence of occult hypoxemia was highest among Black patients (11.4%, 95% CI [4.6, 25.5]; N = 34,869) and Asian, Latino or Hispanic, Native American or Indigenous, or other or mixed race/ethnicity patients (9.7%, 95% CI [3.2, 26.1]; N = 25,130), compared with White patients (6.5%, 95% CI [2.8, 14.2]; N = 109,286). Corresponding prevalence ratios (PRs) are shown in the Figure below. Compared with White patients, the prevalence of occult hypoxemia was 71% greater among Black patients (pooled PR = 1.71, 95% CI [1.43, 2.06]) and 42% greater among Asian, Latino or Hispanic, Native American or Indigenous, or other or mixed race/ethnicity patients (pooled PR = 1.42, 95% CI [1.10, 1.84]). For Black patients, an even larger disparity was apparent at the observation level (pooled PR = 2.04, 95% CI [1.64, 2.54]).

Four studies^2,4,35,44^ reported odds of occult hypoxemia adjusted for potential confounders (in most cases, patient demographics, comorbidities, and therapeutic variables such as use of vasopressors). When results were pooled, Black patients had twice the odds of experiencing occult hypoxemia compared with White patients (aOR = 1.99, 95% CI [1.15, 3.41]; N = 8,410). Reported odds ratios from all studies were similar in magnitude and consistent in direction. Three^2,4,44^ of the 4 studies also included Asian, Latino or Hispanic, Native American or Indigenous, or other or mixed race/ethnicity patients, whose odds of hypoxemia were not significantly greater than those of White participants (aOR = 1.36, 95% CI [0.82, 2.25]; N = 20,536). Most odds ratios in this population were consistent in direction but differed in magnitude. Prevalence ratios and odds ratios followed similar patterns in each group.

Figure Occult Hypoxemia Prevalence Ratios by Patient Race/Ethnicity

Notes. All prevalence ratios use White patients as the reference group, and the dashed line corresponds to a prevalence ratio of 1.0 (no difference in prevalence compared with White patients). N indicates the number of patients in the race/ethnicity group shown and does not include the number of White patients comprising the reference group. Patients reported as Other race/ethnicity are included in the group Asian, Lat./Hisp., NA/Indig (Asian, Latino or Hispanic, Native American or Indigenous).

Most studies providing data on occult hypoxemia prevalence were rated at moderate risk of biased findings for the same reasons as accuracy studies (given the use of accuracy data to define the occult hypoxemia outcome). One study^35^ reporting odds of occult hypoxemia adjusted only for patient sex and measured SpO_2_, compared with the other available studies which controlled for a more comprehensive set of potential confounders. Considering both prevalence and associational findings together, occult hypoxemia is likely more common among Black patients than among White patients (moderate strength of evidence). Asian, Latino or Hispanic, Native American or Indigenous, or other or mixed race/ethnicity patients may also experience occult hypoxemia more frequently than White patients, but the inconsistency of findings across studies and sparse data for some subgroups led us to rate evidence supporting this conclusion as low strength.

One recent study^40^ used approximately 30,000 paired SpO_2_–SaO_2_ observations from patients treated in VHA surgical and general (non-intensive) care settings between 2013 and 2019. The study found larger bias and worse precision in Black VHA patients compared with White patients, and reported prevalences of occult hypoxemia (defined as SaO_2_ less than 88% despite SpO_2_ of 92% or greater) that were among the highest of any included study: 19.6% for Black patients, 16.2% for Hispanic or Latino patients, and 15.6% for White patients. The difference in likelihood of occult hypoxemia between Black patients and White patients remained after controlling for patient sex, age, and comorbidities (p < .001). Investigators also analyzed whether SpO_2_ and SaO_2_ values were consistent across pairs of patient measurements taken the same day. Black patients had a higher likelihood of occult hypoxemia at a second oximetry reading than White patients, even when patients in both groups did not show occult hypoxemia on their first oximetry reading taken the same day (ie, Black patients’ probability of occult hypoxemia was more variable among measurement instances than that of White patients). Data used in the study were drawn from the Corporate Data Warehouse, and in our appraisal, reasonable efforts were made to generate a dataset representative of the general VHA patient population and to limit selection biases that could reduce the generalizability of study findings.

### Clinical Outcomes

We found few studies that examined the association between occult hypoxemia (or differential pulse oximeter accuracy) and clinical outcomes by patient race/ethnicity, and evidence was considered insufficient to make firm conclusions about this relationship. Nonetheless, there does appear to be some signal that Black patients with undetected hypoxemia could experience poorer treatment delivery and clinical outcomes than White patients with undetected hypoxemia.

One multicenter study^46^ in 215 US hospitals and 315 intensive care units reported length of stay and in-hospital mortality by whether patients experienced occult or “hidden” hypoxemia (defined as SaO_2_ less than 88% despite SpO_2_ of 88% or greater in observations separated by no longer than 10 minutes). For Black patients (N = 26,032), occult hypoxemia was associated with significantly shorter length of stay compared with Black patients without occult hypoxemia (−3.0 days, p < .01). Length of stay for White patients (N = 57,623) with occult hypoxemia was also significantly shorter than White patients without occult hypoxemia, but by only 0.5 days on average (p < .01). Length of stay was significantly longer for Asian (N = 1,919) and Hispanic (N = 2,397) patients with occult hypoxemia, but by less than 1 day on average compared with patients without occult hypoxemia. In-hospital mortality was more common in patients experiencing occult hypoxemia regardless of race or ethnicity, with the largest difference among White patients (11.1% greater than White patients without occult hypoxemia, p < .001). Length of stay comparisons were unadjusted, while mortality comparisons were adjusted for patient age, sex, and Sequential Organ Failure Assessment (SOFA) score.

A second study,^2^ which used health record data from 26,603 patients in intensive care or undergoing surgery at 3 US academic medical centers, reported that occult hypoxemia was associated with fewer hospital-free days and greater in-hospital mortality after adjusting for patient age, sex, comorbidities, setting (intensive care unit or surgery), and acuity. Neither outcome significantly differed by patient race or ethnicity, though Black, Asian, or American Indian patients together made up a relatively small proportion of the patient sample (2,110 versus 24,493 White patients). Only simultaneously collected SpO_2_–SaO_2_ readings were used in the study, and occult hypoxemia was defined as SaO_2_ less than 88% despite SpO_2_ of 92% or greater.

A smaller study^1^ in patients evaluated in the emergency department or hospitalized for COVID-19 in the Johns Hopkins Health System (N = 1,903) examined whether patients predicted to have an SaO_2_ of 94% or less prior to a measured SpO_2_ of 94% or less (ie, an unrecognized hypoxemic state) experienced delayed recognition of treatment eligibility or delayed treatment initiation. Failure to recognize eligibility or delayed recognition of eligibility was significantly more likely among both Black patients (adjusted hazard ratio [aHR] = 0.71, 95% CI [0.63, 0.80]) and Hispanic or Latino patients (aHR = 0.77, 95% CI [0.66, 0.89]) with unrecognized hypoxemia compared with White patients with unrecognized hypoxemia. Analyses were adjusted for patient demographics, comorbidities, acuity, and laboratory values (eg, hemoglobin). In the subset of patients eventually recognized as treatment eligible, the median delay to eligibility recognition was about 2 hours longer for Black patients and Asian patients compared with Hispanic or Latino and White patients (see Table above; p = .01 for Black patients versus White patients).

A final observational study^39^ used a causal inference methodology to assess whether differential bias in pulse oximeter measurements led to poorer COVID-19 treatment and health services outcomes for Black patients in a large California integrated health system. Compared with White patients, overestimation of SaO_2_ among Black patients (N = 1,699) was associated with a significantly lower likelihood of hospital admission (−3.1%, 95% CI [−3.4, −2.8]), initiation of treatment with dexamethasone (−3.1%, 95% CI [−3.4, −2.7]), delivery of supplemental oxygen (−4.5%, 95% CI [−4.9, −4.2]), and post-discharge return to the hospital (−1.2%, 95% CI [−1.9, −0.5]). Overestimation of SaO_2_ was predicted to result in a 37-minute delay in dexamethasone initiation (95% CI [20.1, 54.3]) and a 279-minute delay in supplemental oxygen initiation (95% CI [181.0, 376.0]). Results were adjusted for patient age, sex, common comorbidities, and homelessness and insured statuses.

ii Shi et al also pooled studies that reported accuracy by patient pigmentation level (high pigmentation, medium pigmentation, or low pigmentation). Pooled mean bias was largest among patients with high pigmentation (1.11, 95% CI [0.29, 1.93]). Pooled SDs were similar across pigmentation levels and comparable to findings in race/ethnicity groups (1.47 to 1.52).