# METHODS

## REGISTRATION AND REVIEW

A preregistered protocol for this review can be found on the PROSPERO register of systematic reviews (CRD42023402152 (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=402152)). A draft version of this report was reviewed by external peer reviewers; their comments and author responses are located in the Appendix.

## KEY QUESTIONS AND ELIGIBILITY CRITERIA

The following key questions were the focus of this review:

Key Question 1 | Does pulse oximeter accuracy differ by patient race/ethnicity?
Key Question 2 | Does the prevalence or risk of occult hypoxemia differ by patient race/ethnicity?
Key Question 2b | If present, are racial/ethnic disparities in occult hypoxemia associated with differences in treatment delivery or harms?

Eligible studies must have been conducted among adults in inpatient or outpatient healthcare settings. Accuracy studies were required to report paired SpO_2_–SaO_2_ readings measured within 10 minutes of one another. Studies reporting occult hypoxemia prevalence were required to define occult hypoxemia as, at minimum, arterial oxygen saturation ≤ 88% despite a pulse oximeter reading > 88%. Stricter criteria (eg, pulse oximeter reading > 92%) were permitted. Studies that induced hypoxemia in a controlled setting were ineligible. We considered evidence on clinical outcomes (treatment delivery or harms) of occult hypoxemia only when studies reported within-group comparisons by occult hypoxemia status. For example, we included studies that examined whether there was a relationship between occult hypoxemia and in-hospital mortality by comparing patients of the same race or ethnicity with and without occult hypoxemia (then examined whether this relationship differed across race/ethnicity groups), but we did not include studies that investigated whether in-hospital mortality differed by patient race or ethnicity in general.

## SEARCHING AND SCREENING

A research librarian searched Ovid MEDLINE, CINAHL, Scopus, the Cochrane Database of Systematic Reviews, and AHRQ and HSR&D databases for relevant studies published through February 2023 (see Appendix for complete search strategies). Additional citations were identified by hand-searching reference lists. English-language titles, abstracts, and full-text articles were independently reviewed by 2 investigators, and disagreements were resolved by consensus.

## DATA ABSTRACTION AND RISK OF BIAS ASSESSMENT

Participant characteristics, study methodological details, and outcome data were abstracted from all included studies. The internal validity (risk of bias) of included studies was rated using tools appropriate to each study type: the ROBIS^9^ tool for systematic reviews, the QUADAS-2^10^ tool for studies providing accuracy data, and the QUIPS^11^ tool for studies of occult hypoxemia prevalence or occult hypoxemia as a risk factor for downstream clinical outcomes. Potential biases in prevalence estimates were captured in the prognostic factor measurement domain of the QUIPS tool; we supplemented criteria for this domain with biases specific to prevalence assessment.^12^ Risk of bias rating and data abstraction were first completed by 1 investigator then checked by another, and disagreements were resolved by consensus. See Appendix for complete risk of bias ratings.

## SYNTHESIS

When 3 or more sufficiently comparable studies were available, study findings were pooled using random-effects meta-analysis. We identified a well-conducted systematic review and meta-analysis of pulse oximeter accuracy by Shi et al,^6^ which synthesized accuracy data available through mid-2021. To expedite the present review, we took the approach of updating this review with the most recent evidence available. This involved pooling mean bias and precision data from studies published since the end search date of the review (replicating the methods used by Shi et al), then synthesizing the pooled estimates from new evidence with those reported in the existing review. Each of these steps is described in detail below. To harmonize risk of bias ratings, we also re-assessed risk of bias of studies included in the existing systematic review using the approach described above.

For newly identified studies, we first adjusted reported standard deviations (SDs) for each race/ethnicity group in each study using the formula shown below.^13^ The purpose of this adjustment, which was also implemented by Shi et al, was to produce more conservative estimates of precision that account for repeated observations of the same patient. The number of paired oximetry measurements per patient was calculated by dividing the total number of oximetry measurements by the number of patients (eg, in a group of 50 patients in which 500 paired measurements were collected, the approximate number of measurements per patient would be 500/50 = 10 measurements).

A d j u s t e d S D = sqrt(R e p o r t e d S D^2^ × ( (T o t a l M e a s u r e m e n t s − 1)/(T o t a l M e a s u r e m e t n s − M e a s u r e m e n t s p e r P a t i e n t) ))

We also replicated the use of hierarchical random-effects models, cluster-robust confidence intervals, and degrees of freedom calculated using the Satterwaithe approximation. These approaches better account for dependency among estimates; that is, when estimates from the same study are more similar than they would be if they were from a different study and patient sample. The final stage of analysis of mean bias and precision data was to synthesize pooled estimates reported by Shi et al with those from new studies. We implemented the recommendation of Tang et al^14^ for updating a meta-analysis with new results based on comparable methods, which was to use a fixed-effect model to synthesize the final pooled estimates (ie, a pooled estimate corresponding to all evidence prior to September 2021 from Shi et al, and a pooled estimate of evidence from September 2021 through February 2023).

To synthesize occult hypoxemia prevalence estimates, we used meta-analytic generalized random-effects logistic models or hierarchical approximations when dependent prevalence estimates were available. Prevalence estimates were transformed using the standard logit transformation for analysis, and back-transformed for interpretation and reporting. To facilitate comparison of occult hypoxemia prevalences between race/ethnicity groups, we also calculated and synthesized prevalence ratios (PRs). Conventional random-effects models were used to pool PRs^i^ as well as adjusted odds ratios (aORs) of occult hypoxemia by race/ethnicity group. Models incorporated the Knapp-Hartung adjustment to better account for uncertainty in heterogeneity estimation,^15,16^ and when necessary, we used methods for handling dependent data comparable to those described above.

For all analyses, heterogeneity was estimated using (restricted) maximum-likelihood estimation and is presented as 95% prediction intervals (PIs). Prediction intervals describe the likeliest range of true effects (eg, true occult hypoxemia prevalence) across studies and provide an estimate of the magnitude and direction of effects that would be found in future studies similar to those included in a synthesis.^17^ All meta-analyses were conducted using the metafor^18^ package for R (R Foundation for Statistical Computing, Vienna, Austria). When fewer than 3 comparable studies were available for a given outcome—or studies were judged to be too disparate in methodological or participant characteristics—we described evidence narratively.

For the purposes of synthesizing and reporting findings, the consensus reached among investigators was that the following categorizations best balanced data availability with variation in race/ethnicity groups reported across studies: Patients described as Black or African American (“Black”), patients described as White or Caucasian (“White”), and patients described as Asian, Latino or Hispanic, Native American or Indigenous, or other or mixed race/ethnicity. Where possible, we disaggregated findings for the latter group by specific race or ethnicity identities. Studies also varied in whether prevalence of occult hypoxemia was reported by patients or by paired observations. We synthesized each type of prevalence estimate separately. Finally, for consistency with existing literature on pulse oximeter accuracy, we also report A_RMS_ values calculated from pooled mean bias and precision results. It is important to note, however, that interpretation of A_RMS_ is not straightforward: A value between 2–3%, for example, equates to roughly 66% of SpO_2_ readings being within 2–3% of corresponding SaO_2_ readings and 95% being within 4–6% of SaO_2_ readings.^8^

### Strength of Evidence

After synthesizing available evidence, we rated the strength of evidence for each outcome based on the methodology and risk of bias of available studies, the consistency and certainty of findings, and the directness of outcomes (whether reported outcomes are relevant to patients and providers). We used the following general algorithm: high strength evidence consisted of multiple, large studies with consistent and precise findings at low risk of bias, and clinically relevant outcomes; moderate strength evidence consisted of multiple studies with consistent and precise findings at low to moderate risk of bias, and clinically relevant outcomes; low strength evidence consisted of a single study, or multiple small studies, with moderate to high risk of bias, inconsistent or imprecise findings, and/or outcomes with limited clinical relevance; and insufficient evidence consisted of a single study with moderate or high risk of bias, or no available studies. Conclusions using likely (eg, “Pulse oximeters likely overestimate Black patients’ blood oxygen saturation level”) are based on moderate strength evidence, while those using may are based on low strength evidence.

i We chose standard random-effects models over more complex options (eg, log-binomial models) for prevalence ratios because: 1) overall, occult hypoxemia was fairly rare, and therefore logarithms of prevalence ratios and odds ratios would be expected to have similar analytic properties; 2) no studies reported zero occult hypoxemia events, meaning we were not required to use continuity corrections to carry out standard random-effects modeling (analysis in “one step” using log-binomial or similar models would be preferable in such a scenario); and 3) the standard approach was more compatible with methods to account for dependency in reported estimates.