# BACKGROUND

Pulse oximeters are used in many clinical settings and provide a rapid and noninvasive means of measuring oxygen saturation. Despite this utility, pulse oximeters may over- or underestimate a patient’s arterial oxygen saturation (SaO_2_). Overestimating oxygen saturation is especially concerning when pulse oximeter readings of peripheral oxygen saturation (SpO_2_) indicate a normal blood oxygen level while a patient is actually in a hypoxemic state—a situation known as occult hypoxemia. Potential clinical impacts of occult or undetected hypoxemia include delayed or inadequate treatment, premature treatment de-escalation or discharge, and ultimately, greater morbidity and mortality.^1,2^

Inaccurate pulse oximeter readings can occur for a variety of reasons, including severe anemia, excessive blood carbon monoxide levels, impaired circulation (hypoperfusion), and patient movement.^3,4^ Because pulse oximeters rely on the transmission of light through the skin to estimate SaO_2_, skin pigmentation level may also influence pulse oximeter accuracy. Differences in pulse oximeter accuracy by patient race/ethnicity have been observed in clinical settings for several decades, but the COVID-19 pandemic has heightened concern that pulse oximeters may routinely be less accurate in patients with darker skin pigmentation. In the United States, the Food and Drug Administration (FDA) regulates pulse oximeter accuracy and recommends that pulse oximeter performance be within 3% of CO-oximetry in arterial blood (as assessed with accuracy root mean square error, or A_RMS_).^5^ A recent synthesis of pulse oximeter accuracy studies published prior to mid-2021 by Shi et al^6^ reported a somewhat larger pulse oximeter A_RMS_ among Black or African American (“Black”) patients compared with White patients (2.3% versus 1.6%).

The COVID-19 pandemic has also drawn attention to whether racial or ethnic minority patients are at greater risk of occult hypoxemia due to pulse oximeter inaccuracy. A widely discussed retrospective study^7^ published in late 2020 analyzed nearly 50,000 paired SpO_2_–SaO_2_ measurements, finding that the prevalence of occult hypoxemia was over 3 times greater among Black patients compared with White patients (11.4% versus 3.4%). In late 2022, the FDA convened a public meeting of its Anesthesiology and Respiratory Therapy Devices Panel in response to ongoing concerns about racial biases in pulse oximeter accuracy and unrecognized hypoxemia. Guidance on the use and interpretation of pulse oximeters was subsequently updated and emphasizes that pulse oximeter readings are estimates of oxygen saturation that provide “more utility for trends over time instead of absolute thresholds” at the individual patient level.^8^

A number of studies of racial or ethnic disparities in occult hypoxemia prevalence have been recently published. Most utilize large health system databases and also report data on pulse oximeter accuracy, which goes some way to addressing the sparsity of accuracy data in racial and ethnic minority patients in the pre-COVID-19 literature reviewed by Shi et al. The aim of the present review was to provide an up-to-date synthesis of evidence on racial and ethnic disparities in the accuracy of pulse oximeters, the prevalence of occult hypoxemia, and clinical outcomes associated with occult hypoxemia. This review was developed in response to a request from the Veterans Health Administration (VHA) National Hospital Medicine Program and Office of Specialty Care Services.