# ABBREVIATIONS TABLE

Abbreviation: Definition
aHR: Adjusted hazard ratio
aOR: Adjusted odds ratio
A_RMS_: Accuracy root mean square error
CI: Confidence interval
FDA: US Food and Drug Administration
IQR: Interquartile range
k: Number of studies
PI: Prediction interval
PR: Prevalence ratio
N: Number of patients
N_Obs_: Number of paired observations
SaO_2_: Arterial oxygen saturation
SD: Standard deviation
SpO_2_: Peripheral oxygen saturation measured by pulse oximetry
VHA: Veterans Health Administration