# References

1 Baumhauer JF, Pinzur MS, Daniels TR, . Survey on the need for bone graft in foot and ankle fusion surgery. Foot Ankle Int. 2013;34(12):1629–1633.23986324
2 Lareau CR, Deren ME, Fantry A, Donahue RM, DiGiovanni CW. Does autogenous bone graft work? A logistic regression analysis of data from 159 papers in the foot and ankle literature. Foot Ankle Surg. 2015;21(3):150–159.26235852
3 Coughlin MJ, Grimes JS, Traughber PD, Jones CP. Comparison of radiographs and CT scans in the prospective evaluation of the fusion of hindfoot arthrodesis. Foot Ankle Int. 2006;27(10):780–787.17054877
4 Krause F, Younger AS, Baumhauer JF, . Clinical outcomes of nonunions of hindfoot and ankle fusions. J Bone Joint Surg Am. 2016;98(23):2006–2016.27926682
5 Yeoh JC, Taylor BA. Osseous healing in foot and ankle surgery with autograft, allograft, and other orthobiologics. Orthop Clin North Am. 2017;48(3):359–369.28577785
6 Wallace GF. Current Orthobiologics for elective arthrodesis and nonunions of the foot and ankle. Clin Podiatr Med Surg. 2017;34(3):399–408.28576198
7 DiGiovanni CW, Lin SS, Daniels TR, . The importance of sufficient graft material in achieving foot or ankle fusion. J Bone Joint Surg Am. 2016;98(15):1260–1267.27489316
8 Thevendran G, Shah K, Pinney SJ, Younger AS. Perceived risk factors for nonunion following foot and ankle arthrodesis. J Orthop Surg. 2017;25(1):2309499017692703.
9 Thevendran G, Younger A, Pinney S. Current concepts review: risk factors for nonunions in foot and ankle arthrodeses. Foot Ankle Int. 2012;33(11):1031–1040.23131455
10 DiDomenico LA, Thomas ZM. Osteobiologics in foot and ankle surgery. Clin Podiatr Med Surg. 2015;32(1):1–19.25440414
11 West TA, Williams ML. Orthobiologics. Clin Podiatr Med Surg. 2019;36(4):609–626.31466571
12 American Academy of Orthopaedic Surgeons. Helping Fractures Heal (Orthobiologics). OrthoInfo Web site. https://orthoinfo.aaos.org/en/treatment/helping-fractures-heal-orthobiologics/. Published 2010. Accessed 17 November 2019.
13 Fitzgibbons TC, Hawks MA, McMullen ST, Inda DJ. Bone grafting in surgery about the foot and ankle: indications and techniques. J Am Acad Orthop Surg. 2011;19(2):112–120.21292934
14 Lin SS, Montemurro NJ, Krell ES. Orthobiologics in Foot and Ankle Surgery. J Am Acad Orthop Surg. 2016;24(2):113–122.26803546
15 Daniels TR, Younger AS, Penner MJ, . Prospective randomized controlled trial of hindfoot and ankle fusions treated with rhPDGF-BB in combination with a beta-TCP-collagen matrix. Foot Ankle Int. 2015;36(7):739–748.25848134
16 DiGiovanni CW, Lin SS, Baumhauer JF, . Recombinant human platelet-derived growth factor-BB and beta-tricalcium phosphate (rhPDGF-BB/beta-TCP): an alternative to autogenous bone graft. J Bone Joint Surg Am. 2013;95(13):1184–1192.23824386
17 Harford JS, Dekker TJ, Adams SB. Bone marrow aspirate concentrate for bone healing in foot and anklesurgery. Foot Ankle Clin. 2016;21(4):839–845.27871416
18 Tufanaru C MZ, Aromataris E, Campbell J, Hopp L. Chapter 3: Systematic reviews of effectiveness. In: Aromataris E MZ, ed. Joanna Briggs Institute Reviewer’s Manual: The Joanna Briggs Institute, 2017. Available from https://reviewersmanual.joannabriggs.org/ (Accessed October 2, 2019)
19 Moola S MZ, Tufanaru C, Aromataris E, Sears K, Sfetcu R, . Chapter 7: Systematic reviews of etiology and risk. In: Aromataris E MZ, ed. Joanna Briggs Institute Reviewer’s Manual: The Joanna Briggs Institute; 2017. Available from https://reviewersmanual.joannabriggs.org/ (Accessed October 2, 2019)
20 Abd-Ella MM, Galhoum A, Abdelrahman AF, Walther M. Management of nonunited talar fractures with avascular necrosis by resection of necrotic bone, bone grafting, and fusion with an intramedullary nail. Foot Ankle Int. 2017;38(8):879–884.28587485
21 Anderson J, Jeppesen N, Hansen M, Brady C, Gough A, Fowler Z. First metatarsophalangeal joint arthrodesis: comparison of mesenchymal stem cell allograft versus autogenous bone graft fusion rates. Surgical Science. 2013;4:263–267.
22 Bibbo C, Patel DV, Haskell MD. Recombinant bone morphogenetic protein-2 (rhBMP-2) in high-risk ankle and hindfoot fusions. Foot Ankle Int. 2009;30(7):597–603.19589304
23 Buda M, Hagemeijer NC, Kink S, Johnson AH, Guss D, DiGiovanni CW. Effect of fixation type and bone graft on tarsometatarsal fusion. Foot Ankle Int. 2018;39(12):1394–1402.30175622
24 Cao HH, Lu WZ, Tang KL. Isolated talonavicular arthrodesis and talonavicularcuneiform arthrodesis for the Muller-Weiss disease. J Orthop Surg Res. 2017;12(1):83.28583192
25 Chahal J, Stephen DJ, Bulmer B, Daniels T, Kreder HJ. Factors associated with outcome after subtalar arthrodesis. J Orthop Trauma. 2006;20(8):555–561.16990727
26 Chen YJ, Huang TJ, Shih HN, Hsu KY, Hsu RW. Ankle arthrodesis with cross screw fixation. Good results in 36/40 cases followed 3–7 years. Acta Orthop Scand. 1996;67(5):473–478.8948253
27 Easley ME, Trnka HJ, Schon LC, Myerson MS. Isolated subtalar arthrodesis. J Bone Joint Surg Am. 2000;82(5):613–624.10819272
28 Fourman MS, Borst EW, Bogner E, Rozbruch SR, Fragomen AT. Recombinant human BMP-2 increases the incidence and rate of healing in complex ankle arthrodesis. Clin Orthop Relat Res. 2014;472(2):732–739.23990449
29 Grunander TR, Thordarson DB. Results of calcaneocuboid distraction arthrodesis. Foot Ankle Surg. 2012;18(1):15–18.22325997
30 Holm JL, Laxson SE, Schuberth JM. Primary subtalar joint arthrodesis for comminuted fractures of the calcaneus. J Foot Ankle Surg. 2015;54(1):61–65.25176004
31 Lechler P, Graf S, Kock FX, Schaumberger J, Grifka J, Handel M. Arthrodisis of the talonavicular joint using angle-stable mini-plates: a prospective study. Int Ortho. 2012;36:2491–2494.
32 Patil S, Auyeung J, Gower A. Outcome of subtalar fusion using bovine cancellous bone graft: a retrospective case series. J Foot Ankle Surg. 2011;50(4):388–390.21616686
33 Plaass C, Knupp M, Barg A, Hintermann B. Anterior double plating for rigid fixation of isolated tibiotalar arthrodesis. Foot Ankle Int. 2009;30(7):631–639.19589309
34 Rearick T, Charlton TP, Thordarson D. Effectiveness and complications associated with recombinant human bone morphogenetic protein-2 augmentation of foot and ankle fusions and fracture nonunions. Foot Ankle Int. 2014;35(8):783–788.24850162
35 Rungprai C, Phisitkul P, Femino JE, Martin KD, Saltzman CL, Amendola A. Outcomes and complications after open versus posterior arthroscopic subtalar arthrodesis in 121 patients. J Bone Joint Surg Am. 2016;98(8):636–646.27098322
36 Sun L, Kong Z, Xu M. Minimally invasive subtalar arthrodesis for traumatic subtalar arthritis. J Int Med Res. 2019;47(12):6129–6138.31179806
37 Weinraub GM, Schuberth JM, Lee M, . Isolated medial incisional approach to subtalar and talonavicular arthrodesis. J Foot Ankle Surg. 2010;49(4):326–330.20610201
38 Wheeler J, Sangeorzan A, Crass SM, Sangeorzan BJ, Benirschke SK, Hansen ST. Locally generated bone slurry accelerated ankle arthrodesis. Foot Ankle Int. 2009;30(7):686–689.19589317
39 Yavuz U, Sokucu S, Demir B, Ozer D, Ozcan C, Kabukcuoglu YS. Isolated subtalar fusion for neglected painful intra-articular calcaneal fractures. Acta Orthop Traumatol Turc. 2014;48(5):541–545.25429580
40 Yildirim T, Sofu H, Camurcu Y, Ozcan C, Oner A, Sahin V. Isolated subtalar arthrodesis. Acta Orthop Belg. 2015;81(1):155–160.26280869
41 Muller MA, Frank A, Briel M, . Substitutes of structural and non-structural autologous bone grafts in hindfoot arthrodeses and osteotomies: a systematic review. BMC Musculoskelet Disord. 2013;14:59.23390993
42 DeOrio JK, Farber DC. Morbidity associated with anterior iliac crest bone grafting in foot and ankle surgery. Foot Ankle Int. 2006;25(2):147–151.
43 Whitehouse MR, Lankester BJ, Winson IG, Hepple S. Bone graft harvest from the proximal tibia in foot and ankle arthrodesis surgery. Foot Ankle Int. 2006;27(11):913–916.17144952
44 Baumhauer J, Pinzur MS, Donahue R, Beasley W, DiGiovanni C. Site selection and pain outcome after autologous bone graft harvest. Foot Ankle Int. 2014;35(2):104–107.24227683