# Summary and Discussion

## Key Findings

Accurately assessing effectiveness of orthobiologics is not possible due to poor methodological quality of studies. Most reports were small retrospective chart review studies with little controlling for patient factors (eg, health status, medications, severity of presentation) likely to affect intervention indication or effectiveness.

1. No studies were designed specifically to assess the effect of orthobiologics versus no orthobiologics on outcomes following foot and ankle arthrodesis. All studies evaluating orthobiologic effectiveness as a primary study objective were retrospective.
2. Orthobiologics were typically used at a surgeon’s discretion for patients judged to be at higher risk for non-union (eg, large bone defects, malalignment, or patient health-related factors).
3. The greatest amount of information is on bone grafts. There is extremely limited information on other orthobiologics for foot and ankle arthrodesis.
4. All studies reported either radiographic or CT fusion, or time to fusion, and nearly half reported a measure of function or quality of life. Other outcomes of interest were infrequently reported, including donor site morbidity.
5. Few studies reported significant differences in outcomes between patients receiving orthobiologics and those not receiving orthobiologics, though most studies were small and statistically significant results could not be ruled out.
6. Evidence was insufficient to assess whether effectiveness of orthobiologics varied by patient age, gender, smoking status, obesity, diabetes, bone quality, arthrodesis site, or use of medications that may impede healing due to limited reporting. Several studies addressed risk factors for healing but did not report results for orthobiologic and no orthobiologic subgroups.
7. Evidence was insufficient to assess costs or cost-effectiveness of orthobiologics. Two studies reported operation time, finding longer times for procedures involving graft harvest but no difference in operation time when non-graft orthobiologic products were used.
8. Although randomized trials are the gold standard for effectiveness research, a randomized trial would be difficult due to variability in patient health and bone structure factors.
9. Data registries, including VA-NSQIP in combination with other VA databases, might provide useful information by evaluating outcomes after carefully controlling for patient factors likely to influence intervention indication and outcomes. It may be possible to also merge this information with VA cost data to more accurately assess the cost, cost-effectiveness, and budget impact of orthobiologics.
10. Some orthobiologics may be effective in, and are FDA-approved for, spinal fusions or open tibial fractures. It is not known if these findings are applicable to foot and ankle arthrodesis.
11. Given the current evidence, we suggest consideration of utilization review and approval prior to use. This would focus orthobiologic use and a potential second surgical procedure on patients and/or arthrodesis sites of greatest risk of nonunion. Providers and policymakers should be aware of the cost and possible morbidity associated with widespread use of orthobiologics given the insufficient to low-strength evidence of benefit – in particular, mostly radiographic rather than clinical outcomes.

## Discussion

No orthobiologic can replace good surgical technique and good academic decision-making.^10^ Surgeons can optimize success by taking into consideration the risk factors for nonunion when selecting patients for orthobiologics, emphasizing the importance of compliance with post-surgery protocols, and using sound surgical principles such as careful preparation of opposing bone surfaces, compression across the arthrodesis site, and external fixation where needed.^6,13^

As new orthobiologics are introduced (likely at higher costs), surgeons need to critically analyze any product information and research results including risks, benefits, cost, surgical complexity (including the possibility of an additional surgical procedure for bone graft harvesting that may involve donor site morbidity), and volume of material available.^6,11,13^ There is a need for more rigorous outcome data to compare fusion rates of each product as well as one product versus another and different products within the same class (different due to proprietary manufacturing processes).^6^

A survey of North American and Canadian orthopedic foot and ankle surgeons was designed to determine clinical and radiographic factors associated with the decision to use supplemental bone graft.^1^ The survey was completed by 48 of 66 (73% response rate) surgeons (representing academic and private practice) who received the survey. It is important to note that the surgeons were all involved in a large clinical trial of an autograft substitute. The most frequently reported clinical factors were nonunion (ie, regarding use of graft in a revision surgery), nonunion of an adjacent joint, smoking history, use of medications known to interfere with bone healing, and vitamin D deficiency. Frequently reported radiologic factors included nonunion, avascular necrosis, evidence of potential incongruous apposition, radiographic evidence of bone loss, osteoporosis, or post-trauma with subchondral collapse. There was variation in the sample with regard to the weighting of the clinical and radiographic factors when deciding whether to use bone graft although all surgeons reported that they considered both types of information to some degree.

Two recent systematic reviews noted that few studies reported on use of autograft versus no autograft.^2,41^ Müller et al included studies comparing cortical or cancellous autologous bone grafts with any structural or non-structural substitute.^41^ Both prospective and retrospective controlled trials were included provided a minimum of 20 patients were enrolled. The review included 10 studies; quality was low. The authors concluded that “structural allografts appear to be at least non-inferior to autologous grafts” for union in hindfoot arthrodesis but called for RCTs with larger sample sizes. Only one of the studies from the Müller et al review, a study that also included a non-graft group,^27^ was included in our review.

Lareau et al included 159 papers reporting union and nonunion rates associated with the use of autograft, allograft, or no bone graft in arthrodesis, osteotomies, and treatment of nonunions.

They excluded studies that supplemented bone graft insertion with a bone graft substitute or other orthobiologic, studies in children younger than 10 years of age, non-English language articles, case reports with fewer than 4 patients, and use of xenograft or any vascularized bone graft.^2^ Of relevance to our review, the authors presented data from 2213 patients in 70 studies who received cancellous autograft and from 1208 patients in 50 studies who did not receive a bone graft. Relative to no graft, the odds ratio for union with cancellous autograft was 1.39 (95%CI 0.92, 2.1; P=.11). The probability of union was 93.7% with cancellous autograft and 91.4% for no graft. When the analysis was limited to studies with both cancellous autograft and no graft groups, the union rates were 95.1% and 91.9% for cancellous autograft and no graft, respectively. The odds ratio was 1.79 (95%CI 0.91, 3.3; P=.09). The authors did not provide results by type of surgical procedure. They also attempted to evaluate the potential impact of patient risk factors and fusions sites on union rates but found that primary studies did not report data in a way that would allow that analysis.

### Randomized Controlled Trials

We found no RCTs comparing use of an orthobiologic to no orthobiologic. We did identify 2 RCTs, both non-inferiority studies, in patients undergoing hindfoot or ankle arthrodesis. In the first study, patients (n=434) requiring non-structural supplemental bone graft (<9 cc) as part of the arthrodesis procedure were randomized to receive either recombinant human platelet-derived growth factor-BB (rhPDGF-BB) homodimer combined with beta-tricalcium phosphate (β-TCP) or autograft.^16^ The autografts were harvested from separate surgical sites. CT-confirmed fusion rates at 24 weeks post-surgery, the primary effectiveness outcome, were similar for the 2 groups. The groups were also comparable on other clinical outcomes including function and quality of life. There was less pain and fewer adverse events in the rhPDGF-BB/β-TCP group. The second study evaluated an injectable form of rhPDGF-BB/β-TCP.^15^ In this study, 75 patients were randomized in a 5:1 ratio to rhPDGF-BB/β-TCP or autograft. An additional 142 patients who received autografts in the earlier RCT^16^ were included as historical controls. The primary outcome (CT-confirmed fusion at 24 weeks) was similar for the 2 groups. Mean time to fusion was shorter in the rhPDGF-BB/β-TCP group. Non-inferiority was also demonstrated for pain, function, quality of life, and safety measures.

### Donor Site Morbidity

A commonly cited concern with bone graft harvesting is donor site morbidity including infection, prolonged wound drainage, sensory loss, and pain.^13^ Only one of our included studies reported a measure of donor site morbidity. Several case series, without a no-orthobiologic comparator, have assessed morbidity associated with graft harvest. In a retrospective study from the US, DeOrio and Farber included data from 180 patients with an iliac crest bone graft harvest procedure for foot and ankle surgery.^42^ From the medical records, there were no major complications and 17 (9.5%) with minor complications – 12 with hematoma or seroma, 3 with lateral femoral cutaneous nerve irritation, 1 partial wound dehiscence, and 1 superficial wound infection. No extra hospital days were required, and no deep infections were reported. At a mean follow-up of 6 years (range 1 to 13), 134 of 169 (79%) of patients were able to be contacted. Of the 134 contacted, 120 (90%) reported no pain at the graft site. Among the 120 patients, 57% reported greater postoperative pain at the foot or ankle surgical site than at the harvest site; 27% reported greater postoperative pain at the harvest site than at the foot or ankle surgical site; and 16% reported that the postoperative pain was equal at the 2 sites.

A retrospective study from the United Kingdom focused on proximal tibia grafts for 148 foot and ankle arthrodesis procedures in 131 patients.^43^ The mean time from surgery was 28 months (range 3 to 69 months). On a scale of 1 (no pain) to 5 (severe pain), the mean pain level post-surgery was 1.25. At follow-up, the mean was 1.04. No patient reported moderate or severe pain at any time. Four reported mild pain and 29 reported very mild pain initially with none reporting mild pain and 6 reporting very mild pain at follow-up. Post-operative paresthesia was reported in 8 patients (5.4%) with 4 resolved at follow-up. The single case of early superficial wound infection also resolved. There were no reported cases of hematoma or fracture.

Patients in the autograft group from the RCT comparing rhPDGF-BB/β-TCP to autograft^16^ were assessed for harvest site pain during study follow-up.^44^ The harvest site was selected by the study surgeons with 13% iliac crest, 51% proximal tibia, 18% distal tibia, and 15% calcaneus. Pain was assessed on a 100-point visual analog scale (VAS) with scores of 20 or higher indicating clinically significant pain. Post-surgery, the mean pain score was 32.9 with 49 patients (35.8%) reporting clinically significant pain at the harvest site. At 52 weeks, the mean score was 6.1 with 11 patients (8.5%) reporting clinically significant pain. The percentage of patients reporting clinically significant pain at 52 weeks was 0% for the iliac crest site, 13% for the distal tibia, 6% for the proximal tibia, and 20% for the calcaneus.

## Limitations

In addition to limitations related to study design and sample size listed above, there are several other limitations of the available evidence.

1) The majority of studies assessed union rates using radiographs alone. In a previous case series, poor agreement was reported when radiographs and CT scans were used to determine the percentage of fusion following hindfoot arthrodesis involving the subtalar or a combination of the subtalar, talonavicular, and calcaneocuboid joints.^3^ Assessments based on standard radiographs generally overestimated the degree of joint fusion in comparison to assessments based on the CT scans.
2) Few studies reported patient-centered outcomes such as pain, function, quality of life, or need for reoperation.
3) No studies reported costs. For autograft, costs will vary depending on the harvest site. A second surgical procedure, possibly involving a second surgeon, will likely increase operating room time and related costs. For manufactured products, costs vary, with higher costs for products containing living cells (eg, allograft with stem cells) and lower cost for bone products such as DBM. Cost also varies depending on the volume of product needed.

## Applicability of Findings to the VA Population

None of the included studies was conducted specifically with a VA population. Eleven of the 21 studies were from the US. Overall the mean age of patients included in the studies was 50 years with 55% male.

Based on the current state of evidence, we suggest consideration of utilization review and approval prior to use. This would focus orthobiologic use and a potential second surgical procedure on patients and/or arthrodesis sites of greatest risk for nonunion. Providers and policy makers should be aware of the cost and possible morbidity associated with widespread use of orthobiologics given the insufficient to low-strength evidence of benefit – in particular, mostly radiographic rather than clinical outcomes. Furthermore, clinicians and patients should be aware that orthobiologic products are not specifically approved for use in foot and ankle arthrodesis. Thus, the clinical effectiveness, harms, and costs for foot and ankle arthrodesis are not well known and use of these products for these indications is considered “off label”.

## Research Gaps/Future Research

Existing studies for the comparison of an orthobiologic to no orthobiologic are largely retrospective chart reviews. Few of the identified risk factors for nonunion (eg, smoking status, diabetes) were captured in the chart reviews. Selection bias, with surgeons electing to use an orthobiologic for more complex cases (eg, bone defects, high risk for nonunion), is also a concern.^1,5^ There is limited evidence on specific indications for orthobiologic use during arthrodesis. Additionally, there is little information on cost of the products and cost/morbidity including donor site morbidity if autografts are used.

Future research should include standardized methods for processing and preparation of orthobiologics to allow for comparisons between studies. Outcome assessment should be standardized including protocols for capturing radiographic or CT images and measures of what constitutes fusion. Patient-centered outcomes should be captured and studies should include longer-term monitoring to capture adverse events.^11^

## Conclusions

The available evidence is of poor quality due to study designs with high potential for selection bias; small sample sizes; inadequate reporting of patient and surgical risk factors for nonunion; and variations in populations studied, orthobiologics and surgical techniques used, and outcome assessment. As a result, there is very little evidence to inform surgeons regarding which patients might benefit most from orthobiologics or which orthobiologic to use. The absence of evidence that use of orthobiologics is superior to no orthobiologics suggests that a careful assessment of individual patient risk for nonunion is critical prior to orthobiologic use and that patients and clinicians should be informed that use of orthobiologics for foot and ankle arthrodesis is considered “off-label”.