# Results

## Literature Flow

Figure 2 depicts the results of our abstract and full-text article review process. Our search of multiple databases yielded 1,651 citations. Removing duplicates resulted in 1,564 abstracts for review. Of those, 282 were identified for full-text review along with 2 articles identified from hand-searching. We excluded 263 articles, many of which involved a surgical procedure that was not of interest for our review or that did not have a no-graft comparator group, and included 21.

Figure 2 Literature Flow Chart

## KEY QUESTION 1 What are the effectiveness and harms of adding orthobiologics compared to no orthobiologics when performing primary foot/ankle arthrodesis surgery?

## KEY QUESTION 1A Do effectiveness and harms vary by patient age, gender, smoking status, obesity, diabetes, bone quality, arthrodesis site, or use of medications that may impede healing (eg, immunosuppressives)?

### Summary of Findings

Accurately assessing the effectiveness of orthobiologics is not possible due to poor methodological quality of studies. Most reports were small retrospective chart review studies with little controlling for patient factors (eg, health status, medications, severity of presentation) likely to affect intervention indication or effectiveness. No studies were designed specifically to assess the effect of orthobiologics versus no orthobiologics on outcomes following foot and ankle arthrodesis. Orthobiologics were typically used at a surgeon’s discretion for patients judged to be at higher risk for non-union (eg, large bone defects, malalignment, or patient health-related factors). Few studies reported significant differences in outcomes between patients receiving orthobiologics and those not receiving orthobiologics, though most studies were small and statistically significant results could not be ruled out. Evidence was insufficient to assess whether effectiveness of orthobiologics varied by patient age, gender, smoking status, obesity, diabetes, bone quality, arthrodesis site, or use of medications that may impede healing due to limited reporting.

### Overview of Studies

We identified 21 studies that reported a comparison of an orthobiologic to no orthobiologic in foot and ankle arthrodesis.^20,21,22–26,27,28,29,30,31,32–36,37,38,39,40^ Orthobiologics included autologous bone graft or slurry and recombinant human bone morphogenetic protein (rhBMP-2), demineralized bone matrix (DBM), or platelet products alone or in combination with autologous graft (Table 1). The number of subjects ranged from 9 to 133, mean age was 50 years (range 28–62 years), 55% were male (range 13–80%), and follow-up periods ranged from 3 to 78 months (mean 32 months). Three studies reported that patients were followed until union.^21,22,34^ There were 11 studies from the US, 5 from Asia, 3 from Europe, and 1 from Canada. One study did not report where the procedures were performed.^20^ Additional study information including inclusion/exclusion criteria, description of the orthobiologics, and patient demographics is presented in Appendix D, Table 1.

Included studies were predominantly retrospective chart reviews; 4 provided a retrospective analysis of prospectively enrolled cases.^20,31,33,36^ Seven studies, 5 using autologous bone graft or slurry,^21,25,27,38,40^ 1 using rhBMP-2,^28^ and 1 using DBM,^23^ reported that an objective of the study was to evaluate the use of an orthobiologic.

Table 1 Orthobiologics and Number of Studies

Orthobiologic | Number of Studies | Sample Size Total (range) | Age (mean) | % Male (mean)
Autologous bone graft vs no graft | 10 | 469 (9–133) | 48 | 53
Remote autologous graft vs local graft | 2 | 32 (15–17) | 53 | 56
Local bone slurry vs no slurry | 1 | 54 | 52 | 65
rhBMP-2 + graft vs rhBMP-2 only | 2 | 117 (48–69) | 52 | 56
DBM + graft vs no graft | 1 | 88 | 57 | 20
Platelet products + femoral head allograft vs femoral head allograft | 1 | 14 | 43 | 71
rhBMP-2 vs no orthobiologic | 1 | 82 | 57 | NR
DBM, Platelets, or BMP alone or in combination (some with bone graft) vs no orthobiologic | 3 | 113 (16–57) | 51 | 68 (2 studies reporting)

BMP=bone morphogenetic protein; DBM=demineralized bone matrix; NR=not reported

Table 2 provides an overview of the outcomes reported. All studies reported either fusion or time to fusion. Although we identified fusion as an intermediate outcome that would likely affect patient-centered outcomes such as pain, function, quality of life, and need for reoperation, there is consensus that fusion is an appropriate indicator of intervention effectiveness. A measure of functional ability or quality of life was reported in 10 of the 21 studies. Other outcomes of interest were rarely reported including need for reoperation (or amputation), wound complications or infections, and donor site morbidity.

Outcomes reported for each study are presented in Table 3. The studies are grouped by the orthobiologic/non-orthobiologic used. A check mark indicates that the outcome was reported by that study. An arrow indicates the direction of the effect with a neutral arrow (↔) signifying no difference between the orthobiologic and non-orthobiologic groups. Outcomes data for each study are reported in Appendix D, Tables 3–7.

Table 2 Orthobiologics and Outcomes Reported

Orthobiologic (Number of Studies) | Wound Healing | Need for Reoperation | Pain | Function or QoL | Fusion | Time to Fusion | Costs (patient or facility) | Wound Complications/Infection | Donor Site Morbidity
Bone Graft vs no Graft (10) | 1 | 2 | 2 | 8 | 9 | 5 | | 2 | 1
Remote Graft vs Local (2) | 1 | | 1 | 1 | 2 | 1 | 1
Bone Slurry vs No Slurry (1) | | 1 | | | 1
rhBMP-2 + Graft vs rhBMP-2 (2) | | | | | 1 | 2
DBM + Graft vs No Graft (1) | | | | | 1
PRP vs No PRP (1) | | | | | 1
rhBMP-2 (1) | | | | | 1 | | | 1
Mixed Products (3) | 1 | | 2 | 1 | 3 | 3 | 1 | 1
TOTALS | 3 | 3 | 5 | 10 | 19 | 11 | 2 | 4 | 1

Other outcomes extracted: Mortality (no studies reporting), Amputation (2 studies reporting); Minimal Clinically Important Differences for Function or Quality of Life (no studies reporting)

BMP=bone morphogenetic protein; DBM=demineralized bone matrix; PRP=platelet-rich plasma; QoL=quality of life

#### Fusion/Time to Fusion

Fifteen of 19 studies reporting rate of fusion found no difference in fusion rates between the orthobiologic and non-orthobiologic groups. Studies used different methods of assessing fusion (eg, x-ray, CT, clinical) and had different criteria for defining fusion (Appendix D, Table 5). Three studies reported higher fusion in the orthobiologic group, including 1 that compared autologous bone graft with or without DBM to no graft (93% vs 72%),^23^ and 1 that compared rhBMP-2 to no rhBMP-2 (92% vs 82%).^28^ The third study reported a higher percentage of bridging with local bone slurry vs no slurry (94% vs 76%).^38^ One study reported significantly fewer fusions (ie, more nonunion) in a group treated with rhBMP-2 plus autograft compared to rhBMP-2 only (79% vs 100%).^34^

Table 3 Orthobiologics – Summary of Outcomes

Author, Year, Study Design, Sample Size | Site(s) | Orthobiologic(s); Non-Orthobiologic | Wound Healing | Need for Reoperation/Reintervention | Pain | Function/QoL (MCID) | Function/QoL Scale Scores | Radiographic Fusion | Time to Fusion | Costs ([underlined: P]atient/[underlined: F]acility) | Wound Complications/Infection | Mortality | Amputation | Donor Site Morbidity
Bone Graft vs No Graft (k=10)
Abd-Ella, 2017^20^; Prospective Case Series; N=12 | Ankle/subtalar | Autogenous bone graft (n=9); No graft (n=3) | ✓; ↔ | ✓ ^a^ | | | ✓; ↔ | ✓ ^a^ | | | | | | ✓; ↔
Anderson, 2013^21^; Retrospective Chart Review; N=114 | First metatarsophalangeal joint | Autograft (local; reduced to cancellous bone chips) (n=62); End-to-end arthrodesis (n=52) | | | | | ✓; ↔ | ✓; ↔ | ✓; ↔
Cao, 2017^24^; Retrospective Chart Review; N=30 | Talonavicular | Autoallergic iliac bone graft (n=5); No bone graft (n=11) | | | | | ✓; ↔ | ✓; ↔
Chahal, 2006^25^; Retrospective Chart Review; N=88 | Isolated subtalar | Local or iliac crest bone graft (n=46); No graft (n=20) | | | | | | ✓; ↔
Chen, 1996^26^; Retrospective Chart Review; N=38 (40 ankles) | Tibiotalar | Tibial condyle graft (n=8 ankles) or sliding graft (n=7 ankles); No graft (n=25) | | | | | ✓; ↔ | ✓; ↔ | | | ✓; ↔ | | ✓; ↔
Easley, 2000^27^; Retrospective Chart Review; N=174 (184 feet) | Isolated subtalar | Cancellous autograft (n=94 feet); No graft (n=39 feet) | | | | | ✓; ↔ | ✓; ↔ | ✓; ↔
Holm, 2015^30^; Retrospective Chart Review; N=17 | Subtalar | Autogenous bone (n=3); No orthobiologic (n=6) | | ✓; ↔ | ✓; ↔ | | ✓; ↔ | ✓; ↔
Lechler, 2012^31^; Prospective Case Series; N=30 | Talonavicular | Autologous spongious bone graft from iliac crest (n=6); No orthobiologic (n=24) | | | ✓; ↔ | | ✓; ↔ | | ✓; ↔
Yavuz, 2014^39^; Retrospective Chart Review; N=20 (21 feet) total | Subtalar | Cancellous autograft (iliac crest) (n=8); No graft (n=9) | | | | | | ✓; ↔ | ✓; ↔ | | ✓; ↔
Yildirim, 2015^40^; Retrospective Chart Review; N=31 (33 feet) total | Subtalar | Autograft (iliac crest) (n=16 feet); No graft (n=14 feet) | | | | | ✓; ↔ | ✓; ↔ | ✓ ^b^; ↓
Remote Graft vs Local Graft (k=2)
Patil, 2011^32^; Retrospective Chart Review; N=26 | Subtalar | Autologous iliac crest bone graft (n=4); Local bone graft (n=13) | | | ✓; ↔ | | | ✓; ↔
Sun, 2019^36^; Prospective Case Series N=15 | Subtalar | Bone graft from iliac crest to supplement local graft (n=4); Local bone (n=11) | ✓; ↔ | | | | ✓; ↔ | ✓; ↔ | ✓; ↔ | ✓ ^c^; ↑
Local Slurry vs No Slurry (k=1)
Wheeler, 2009^38^; Retrospective Chart Review; N=54 | CPT code 27870 (Arthrodesis Procedures on Leg & Ankle Joint) | Local bone slurry (n=32); No slurry (n=22) | | ✓; ↔ | | | | ✓ ^d^; ↑
rhBMP-2 + Graft vs rhBMP-2 only (k=2)
Bibbo, 2009^22^; Retrospective Chart Review; N=69 (112 fusion sites) | Ankle and hindfoot | rhBMP-2 (INFUSE®) and autogenous iliac crest bone graft (n=17 fusions); rhBMP-2 only (n=85 fusions) | | | | | | | ✓; ↔
Rearick, 2014^34^; Retrospective Chart Review; N=48 (51 cases, 83 sites) total | Foot or ankle | rhBMP-2 + autograft (14 sites) (local=11, iliac crest=2, calcaneus=1); rhBMP-2 only (60 sites) | | | | | | ✓ ^e^; ↓ | ✓; ↔
DBM + Graft vs No Graft (k=1)
Buda, 2018^23^; Retrospective Chart Review; N=88 (189 joints) | Tarsometatarsal | Autologous bone graft (n=37); Autologous bone graft + DBM (n=33); No graft (n=18) | | | | | | ✓ ^d^; ↑
Platelet Products (k=1)
Grunander, 2012^29^; Retrospective Chart Review; N=14 (16 feet) | Calcaneocuboid | Femoral head allograft and PRP (n=7 feet); Femoral head allograft alone (n=9 feet) | | | | | | ✓; ↔
rhBMP-2 (k=1)
Fourman, 2014^28^; Retrospective cohort; N=82 | Ankle | rhBMP-2 (n=42); No rhBMP-2 (n=40) | | | | | | ✓ ^d^; ↑ | | | ✓; ↔ | | ✓; ↔
Other/Mixed Products (k=3)
Plaass, 2009^33^; Prospective Case Series; N=29 | Tibiotalar | DBM (n=8) Platelet concentrate (n=1) Both (n=2); No orthobiologic (n=5) | ✓ ^a^ | | ✓ ^a^ | | ✓ ^a^ | ✓; ↔ | ✓; ↔
Rungprai, 2016^35^; Retrospective Chart Review; N=57 (60 feet) | Subtalar | Cancellous autograft (n=12); DBM + allograft (n=12); BMP + allograft (n=12); Platelet concentrator + allograft (n=7); No orthobiologic (n=6) | | | | | | ✓; ↔ | ✓; ↔
Weinraub, 2010^37^; Retrospective Chart Review; N=45 | Combined subtalar and talonavicular | PRP (n=7); PRP/DBM (n=6); DBM (n=5); BMP (n=1); DBM/SC (n=1); PGC (n=1); PRP/SC (n=1); No orthobiologic (n=18) | | | ✓ ^a^ | | | ✓; ↔ | ✓; ↔ | ✓ ^f^; ↔ | ✓; ↔

BMP=bone morphogenetic protein; DBM=demineralized bone matrix; MSC=mesenchymal stem cells; PGC=platelet gel concentrate; PRP=platelet-rich plasma, rhBMP-2=recombinant human bone morphogenetic protein-2; SC=stem cell

a Small n or few events – not able to interpret findings

b Significantly shorter time to fusion with orthobiologic

c Significantly longer operating time for iliac crest graft group

d Significantly greater fusion rate with orthobiologic

e Significantly more nonunions in rhBMP-2 + autograft group; all had history of nonunion

f No difference in surgery duration; no graft harvesting procedures

Including data from all orthobiologic products and arthrodesis sites, fusion rates ranged from 71% to 100% in the orthobiologic group (mean 93%) and from 0% to 100% (mean 85%) in the no-orthobiologic group. Removing one study with a 0% fusion rate in the no-orthobiologic group of 3 individuals,^20^ the range was 44% to 100% (mean 90%) in the no-orthobiologic group.

All but 2 of the 15 studies reporting no difference between study groups reported fusion rates of 85% or higher for both groups. One exception was 1 study of iliac crest or local bone graft versus no graft for 66 isolated subtalar fusions related to primary or secondary osteoarthritis.^25^ Smoking status was not reported for the orthbiologic/non-orthobiologic groups, but overall 43% had smoked at least 1 week before and after surgery. Diabetes was reported in 10% of the population. Fusion rates were 84% in the orthobiologic group and 65% in the non-orthobiologic group. The other exception was a study of PRP with femoral head allograft versus femoral head allograft alone for 14 patients undergoing calcaneocuboid distraction arthrodesis.^29^ Fusion rates were 71% in the PRP group and 44% in the allograft group.

Time to fusion was reported in 11 studies. Three reported that time to fusion did not differ between the orthobiologic and non-orthobiologic groups but did not report actual times.^31,36,39^ For the 8 studies reporting time to fusion, the mean was 12.2 weeks in both the orthobiologic and non-orthobiologic groups.^21,22,27,33–35,37,40^ Only 1 study reported a significant difference in mean time to fusion – 14.4 weeks for 19 patients receiving iliac crest autograft versus 17.5 weeks for 14 patients receiving no graft for subtalar arthrodesis.^40^

#### Patient-centered Outcomes

The most frequently reported patient-centered outcome was a measure of functional status or quality of life (Appendix D, Table 4). None of the 10 studies reporting this outcome found a difference between the orthobiologic and non-orthobiologic groups.^20,21,24,26,27,30,31,33,36,40^ Seven studies reported American Orthopedic Foot and Ankle Society (AOFAS) scores, a measure of function, pain, and alignment.^24,27,30,31,33,36,40^ Three studies assessed patient satisfaction,^20,21,24^ willingness to have the procedure again,^21^ and ability to walk a long distance 6 months post-surgery.^24^ One study used a clinical outcomes rating system.^26^

Other patient-centered outcomes of interest including wound healing, need for reoperation or reintervention, and pain were infrequently reported. Where reported, no differences were observed between the orthobiologic and non-orthobiologic groups (Appendix D, Tables 3 and 4)

#### Harms

Few studies reported harms. Only one study reported donor site morbidity, finding no instances among 12 patients undergoing ankle or subtalar arthrodesis with and without autograft.^20^ Two studies reported amputation with each identifying 1 case in the non-orthobiologic group and no cases in the orthobiologic group, either autograft^26^ or rhBMP-2.^28^ Three studies reported infection with few cases and no significant differences between orthobiologic and nonorthobiologic groups.^26,28,39^

### Quality of Evidence for Key Question 1

We did not formally rate risk of bias or quality of evidence. We evaluated each included study based on critical appraisal criteria for quasi-experimental studies and case series (Appendix B, Appendix D, Table 2). Several characteristics of the studies suggest likely selection and detection bias.

Criteria for inclusion in the study were clearly defined in 16 of 21 studies (76%); however, only 48% (10 studies) reported complete inclusion (ie, including consecutive cases or all cases within a specified time period). Although 7 studies reported that a primary objective of the study was to evaluate the use of an orthobiologic, in 16 studies (76%), patients were treated with an orthobiologic at the surgeon’s discretion – most often due to large bone defects, poor bone alignment, or patient risk factors for nonunion – and the evaluation of orthobiologic use was a retrospective analysis based on whether the product was used during the surgery. The remaining 5 studies did not report a reason why some patients received an orthobiologic and others did not. Only 4 studies (19%) reported that radiographs were reviewed by individuals unaware of whether or not patients received an orthobiologic. Five studies (24%) stated that reviews were not blinded while reporting of blinding/no blinding was unclear in 12 studies (57%). Five studies (24%) used CT scans to confirm fusion observed on radiographs.

## KEY QUESTION 2 What is the cost and/or cost-effectiveness (as reported in the literature) of adding orthobiologics compared to no orthobiologics when performing primary foot/ankle arthrodesis surgery?

### Summary of Findings

We found insufficient evidence to assess costs or cost-effectiveness of orthobiologics. Two studies reported operation time, finding longer times for procedures involving graft harvest but no difference in operation time when non-graft orthobiologic products were used.

#### Operation Time

Only 2 of our included studies reported a cost-related outcome.

One study, conducted in the US, included 40 patients who underwent combined subtalar joint and talonavicular joint arthrodesis.^37^ The group treated with orthobiologics received non-graft products including platelet-rich plasma, demineralized bone matrix, stem cells, and bone morphogenetic protein alone or in combination. The mean duration of surgery ranged from 82 to 98 minutes for surgeries involving an orthobiologic product compared to 83 minutes for surgeries with no orthobiologic product.

A study from China of 15 minimally invasive subtalar arthrodesis procedures performed with local graft or local graft supplemented by graft harvested from the iliac crest reported mean operation times.^36^ The mean operation time for procedures involving iliac crest harvest was longer than the operation time for procedures using only local graft (83.8 minutes vs 50.9 minutes, P<.01).