# Methods

## Topic Development

This topic was nominated by Jeffrey Whitaker, DPM, Chair of the Podiatric Surgery Surgical Advisory Board. The intended usage of the report was to inform best-practice guidelines for podiatric surgery in VHA. With input from Dr. Whitaker and Technical Expert Panel (TEP) members, we developed the key questions and scope for the review.

## Search Strategy

We searched Ovid MEDLINE, Embase, and the Cochrane Library from 1995 to July 2019. The MEDLINE search strategy (Appendix A) included Medical Subject Headings (MeSH) and title/abstract words for orthobiologics (eg, autografts, bone substitutes, platelet-derived growth factor, platelet-rich plasma), foot and ankle site (eg, foot joints, ankle joint) and arthrodesis. Searches of Embase and the Cochrane Library were conducted using similar search strategies. We also searched clinicaltrials.gov for recently completed or ongoing studies and reference lists of relevant systematic and narrative reviews and included studies for articles missed by our literature search.

## Study Selection

Citations were entered into Distiller SR (Evidence Partners). Titles and abstracts were reviewed independently by 2 reviewers with a citation moving to full-text review if either reviewer considered the citation eligible. At full-text review, agreement of 2 reviewers was needed for study inclusion or exclusion. Disputes were resolved by discussion with input from a third reviewer, if needed.

We included randomized or controlled clinical trials, case series with concurrent controls, or pre- to post-intervention studies (eg. interrupted time series) that provided a comparison of the use of an orthobiologic of interest (see below) to no orthobiologic.

### Population

Adults undergoing primary foot/ankle arthrodesis surgery (forefoot to ankle).

### Intervention

Non-structural autogenous orthobiologics (autogenous bone graft, bone marrow aspirate, plasma products); synthetic products.

### Comparator

No orthobiologic. Although we label this as a comparator, the studies included in our review were not designed as comparative studies. Most were retrospective reviews of medical records and study groups consisted of those who received an orthobiologic and those who did not, most often at the surgeon’s discretion.

### Outcomes

- Patient-centered Outcomes: Wound healing, need for reoperation/reintervention, pain, clinically meaningful differences in functional outcome or quality of life scale scores (eg, American Orthopedic Foot and Ankle Society [AOFAS], Mazur).
- Intermediate Outcomes: Radiographic fusion, mean time to union.
- Costs, Cost Effectiveness, Resource Utilization: Patient costs, facility costs.
- Harms: Post-operative complications (eg, scar pain, wound dehiscence, wound complications, neuritis, infection, amputation, malalignment, lateral impingement, mortality, venous thromboembolism); donor site morbidity (eg, hematoma formation, infection, chronic pain, neurological deficits, iatrogenic fractures).

We excluded studies not enrolling a population of interest (eg, Charcot foot, children); not evaluating an orthobiologic of interest; not involving a surgery of interest (eg, revision arthrodesis); involving a comparator other than no orthobiologic; using historical controls; or not reporting outcomes of interest. We also excluded case reports, animal or laboratory studies, papers describing a surgical approach but not reporting outcomes, and non-English publications.

## Data Abstraction

We abstracted study characteristics (inclusion/exclusion criteria, orthobiologic used, patient demographics), patient-centered outcomes, intermediate outcomes, costs, and harms (see above). Studies were organized by orthobiologic used.

## Quality Assessment

We used elements from the Joanna Briggs Institute Critical Appraisal Checklist for Quasi-Experimental Studies^18^ and Critical Appraisal Checklist for Case Series^19^ to assess the quality of the studies (Appendix B). We describe the quality characteristics of the included studies.

## Data Synthesis

Due to differences in orthobiologics used, methods of outcome assessment, and heterogeneity of the included populations (eg, reasons for arthrodesis, arthrodesis site, rationale for receiving or not receiving an orthobiologic), we narratively summarized the findings.

## Rating the Body of Evidence

We did not formally rate the overall body of evidence. We describe limitations of the available evidence.

## Peer Review

A draft version of this report was reviewed by content experts as well as clinical leadership. Reviewer comments and our responses are presented in Appendix C and the report was modified as needed.