# Introduction

Arthrodesis of the ankle, hindfoot, and midfoot joints is an operative treatment for patients with severe pain or disability caused by arthritis, degenerative joint disease, trauma, congenital deformity, Charcot neuropathy, and other conditions.^1,2^ However, reported rates of nonunion following foot and ankle arthrodesis range from 0 to 36% with an average of 10 to 11%.^3–6^ The observed variability is likely due, in part, to varying definitions of nonunion including how nonunion is evaluated (ie, radiographs, computed tomography (CT) scans, or clinically) and the degree of bone bridging required to classify an outcome as union versus nonunion.^3,4,6^

Nonunion following arthrodesis surgery is associated with poor function, disability, and the potential need for revision surgery.^4,7–9^ A number of factors have been reported to be associated with nonunion including patient factors (eg, smoking, diabetes, alcohol consumption, low bone mineral density, age, obesity, rheumatoid arthritis, immunocompromised status, employment status, and certain medications), local factors (eg, infection, vascularity, bone defects or instability at the fusion site soft tissue injury, and revision arthrodesis procedure), and surgical factors (eg, use of sufficient graft material and high-volume vs low-volume surgeons).^4,7–10^

Orthobiologics are biologically derived materials that may be used, in the context of arthrodesis, to promote bone formation and union at the arthrodesis site.^6,11^ Autograft, harvested from the iliac crest, tibia, calcaneus, or other sites, is considered the “gold standard” orthobiologic given that it possesses all 3 of the critical properties for bone healing: osteoconduction (providing a matrix or scaffold), osteoinduction (providing proteins and other factors to stimulate stem cells to differentiate into cells that can form bone), and osteogenesis (bone formation).^2,10,11^ Successful osteoconduction, osteoinduction, and osteogenesis results in osteointegration – the incorporation of the bone graft with the existing bone.^12,13^

Autograft has the advantages of minimizing risk of an immunologic response or infection that might occur with a donor product and is available at no cost (other than costs associated with harvesting the graft). However, the quantity of graft material is limited and there are potential complications including the need for a separate incision site if a distant harvest site is chosen, longer operating time, nerve or vascular damage at the harvest site, and stress risers resulting in increased risk of bone fracture.^2,5,10,11^ To date, there has not been a randomized trial comparing autograft to no graft.^2^

As a result of the potential complications associated with harvesting autograft, other orthobiologic products have been considered for use in arthrodesis. Of interest for this review are non-structural products including osteoinductive products (eg, platelet-derived growth factor [PDGF], demineralized bone matrix [DBM], bone morphogenetic proteins [BMP], platelet-rich plasma [PRP]) and osteogenic products (eg, bone marrow aspirate [BMA]).^5^ Concerns with manufactured products include variability in manufacturing and differences across products in the same class due to proprietary preparation methods.^6,10^

Recombinant human PDGF (rhPDGF-BB), combined with beta-Tricalcium Phosphate (β-TCP) - an osteoconductive material, is a Food and Drug Administration (FDA) approved, bioengineered product for hindfoot and ankle fusions in the US.^5,11,14^ Although there are concerns about the increased risk of cancer based on studies of a topical form of rhPDGF-BB used for chronic wounds (becaplermin gel), recent studies comparing rhPDGF-BB/β-TCP to autograft for hindfoot or ankle arthrodesis found fewer or similar rates of serious treatment-emergent adverse events in the rhPDGF-BB/β-TCP group.^15,16^

DBM is an allograft product developed from bone harvested from cadavers. Through processing, some of the osteoinductive capacity of bone is lost.^5,6^ DBM is used in filling bone defects, often in combination with another material.

BMPs are growth factors that influence the differentiation and proliferation of stem cells to bone-forming cells.^5,6,11,14^ Recombinant human BMPs (rhBMP-2, rhBMP-7) are FDA-approved for use during spinal fusions, open tibial fractures, and long-bone nonunions and have been used off-label for arthrodesis. A major complication of BMP use is heterotopic bone formation, and use of BMPs is not recommended for the cervical spine.

PRP is derived from autologous blood. The end-product contains a highly concentrated volume of platelets that, when activated, release growth factors that promote healing and regeneration of soft tissues and bone.^5,14^ There are many variables involved in the manufacturing process so it is difficult to make comparisons across studies.^6,14^ PRP is not regulated by the FDA.

BMA or BMA concentrate (BMAC) contains stem cells and growth factors.^5,11,17^ Harvesting of BMA is less invasive than graft harvesting. Typical harvest sites are the iliac crest, long bones, or calcaneus.^5^ BMAC may be combined with an osteoconductive material.^11^ The use of BMAC, to date, has largely been in fracture healing.^17^

The purpose of our review was to examine the evidence from studies comparing use of an orthbiologic to no orthobiologic in primary foot (forefoot and proximally) and ankle arthrodesis procedures. Our focus was on non-structural autogenous orthobiologics.

We addressed the following key questions:

1) What are the effectiveness and harms of adding orthobiologics compared to no orthobiologics when performing primary foot/ankle arthrodesis surgery?
  1a) Do effectiveness and harms vary by patient age, gender, smoking status, obesity, diabetes, bone quality, arthrodesis site, or use of medications that may impede healing (eg, immunosuppressives)?
2) What is the cost and/or cost-effectiveness (as reported in the literature) of adding orthobiologics compared to no orthobiologics when performing primary foot/ankle arthrodesis surgery?

The analytic framework (Figure 1) depicts the population, intervention, and outcomes of interest.

Figure 1 Analytic Framework