# APPENDIX D Evidence Tables

Table 1 Study Characteristics

Table 2 Quality Criteria

Table 3 Patient-centered Outcomes, Part 1

Table 4 Patient-centered Outcomes, Part 2

Table 5 Intermediate and Cost Outcomes

Table 6 Harms – Post-operative Complications

Table 7 Harms – Donor Site Morbidity