# APPENDIX C Peer Reviewer Comments and Author Responses

Question Text | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described? | Yes | Thank you
Are the objectives, scope, and methods for this review clearly described? | Yes | Thank you
Are the objectives, scope, and methods for this review clearly described? | Yes | Thank you
Are the objectives, scope, and methods for this review clearly described? | Yes | Thank you
Is there any indication of bias in our synthesis of the evidence? | No | Thank you
Is there any indication of bias in our synthesis of the evidence? | No | Thank you
Is there any indication of bias in our synthesis of the evidence? | No | Thank you
Is there any indication of bias in our synthesis of the evidence? | No | Thank you
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | No | Thank you
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | No | Thank you
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | No | Thank you
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | No | Thank you
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Page 26--lines 22–28. Please note that cost data for biologics can be very difficult for surgeons to obtain from the vendors so it cannot be used in consideration of biologic use.; Page 8--lines 29/30. Is the major complication of joint stiffness related to its use in long bone fracture treatment adjacent to joints, causing the stiffness?; Page 8--line 41--typo? “than”, not then; Page 27--line 57 might read better as--“initial post surgical pain at the foot or ankle” for each example. I had to reread to understand this well.; General questions/comments:; 1. Was Vitamin D a consideration in the reviewed manuscripts? It is often a consideration for revision surgery, but not always looked at prior to the first arthrodesis attempt.; 2. I appreciate the commentary on “selection bias”. This is impossible to avoid in all the case series reports that are available for this review.; 3. I also appreciate the commentary regarding off-label use for certain products. Off label use is a necessary issue with many of these products.; 4. The recommendation for pre-authorization for the biologics appears to be appropriate. The cost of biologics must be more transparent to aid in decision making by the surgeon. | Page 26: We agree that cost data can be difficult for surgeons to obtain and may vary between facilities and over time.; Furthermore, the cost of the product is only one component of the overall cost of care, which includes the possibility for a second surgery or more complex surgical procedure versus improved health outcomes which may both lower future costs as well as improve health outcomes. However, given the limited evidence on effectiveness and the fact that these products are not specifically approved for this indication, clinicians and health systems should be aware that use of these products increases surgical cost and complexity. Health care systems, including the VA, should be more transparent regarding the cost of these products, negotiate lower cost options, and encourage clinician awareness and patient communication of these issues.; Page 8: We modified this statement. Joint stiffness and pain was related to heterotopic bone formation.; Page 8, Line 41: Thank you – changed to “than”; Page 27: Thank you for the suggestion – we revised this sentence.; 1. None of the included studies reported on Vitamin D.; 2,3,4: Thank you. We have added some additional information regarding the importance of cost assessment, negotiation, and awareness for patients, clinicians, and health care systems.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | The use of orthobiologics in foot and ankle surgery is replete of data and controversial. I commend the authors for addressing the lack of knowledge around this topic by performing this exhaustive analysis of controlled studies on the use of orthobiologics. The results of this study are not surprising. Trying to make sense of the ever-expanding orthobiologics world is difficult. The results also indicate the heterogeneous nature of patients presenting for foot and ankle fusions and the hap-hazard nature of implementation of orthobiologics by clinicians. The report also highlights the low incidence of reported (and possibly the actual) harms when using orthobiologics. Finally, the report emphasizes the need for more rigorous studies evaluating the use of orthobiologics. | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | p. 1 line 45 beginning with “Our focus.……” some studies used allografts (bone) which would not be included in this sentence. Should be. | As requested in the topic nomination, our scope was limited to autogenous orthobiologics.