# APPENDIX B Criteria Used in Quality Assessment

We completed a critical appraisal included studies (retrospective chart reviews or prospective case series) based on a modification of the Joanna Briggs Institute 1) Critical Appraisal Checklist for Quasi-Experimental Studies^18^ and 2) Critical Appraisal Checklist for Case Series.^19^ Each item below was rated Yes/No/Unclear/Not Applicable.

Item | Rating
1. Is there evidence of ethical approval for the study?
2. Were there clear criteria for inclusion?
3. Was there complete inclusion of participants?
4. Was there clear reporting of the demographics of the study participants?
5. Were the study groups formed in a way that minimizes bias?
6. Did the participants included in any comparison receive similar treatment/care other than the intervention of interest?
7. Was follow-up complete with no differential follow-up between groups?
8. Was outcome assessment blinded?
9. Were outcomes measured in valid and reliable ways?