# APPENDIX A Search Strategies

## MEDLINE search strategy

exp Transplantation, Autologous/ or exp Autografts/ or exp Bone Transplantation/

exp Bone Marrow Transplantation/ or exp Bone Substitutes/

exp Platelet-Derived Growth Factor/ or exp Platelet-Rich Plasma/

(orthobiologic* or (autologous and graft*) or (autogenous and graft*) or (autogenic and graft*) or autograft* or (iliac and graft*) or (tibia* and graft*) or (calcan* and graft*) or (fibul* and graft*) or “bone graft*”).ti,ab.

(“bone marrow aspirate*” or (bone adj2 transplantation) or “plasma product*” or “platelet-derived” or “platelet derived” or “platelet-rich” or “platelet rich” or “mesenchymal stem cell*” or “bone morphogen* protein*” or PRP or PDGF or MSC or rhPDGF-BB or BMP-2 or rhBMP-2 or BMP-7 or “tricalcium phosphate”).ti,ab.

1 or 2 or 3 or 4 or 5

exp Foot Joints/

exp Foot Bones/

exp Ankle Joint/

(foot or ankle or naviculocuneiform or Lisfranc or Chopart or midfoot or mid-foot or hindfoot or hind-foot or calcaneous or calcaneal or talus or talar or subtalar or tarsal or tibiotalar or tibiotalocalcaneal or calcaneocuboid or talonavicular or mid-tarsal or midtarsal or tarsometatarsal or metatarsophalangeal).ti,ab.

exp Arthrodesis/ or (arthrodes* or fusion* or union* or fixation*).mp.

7 or 8 or 9 or 10

11 and 12

6 and 13

limit 14 to “all child (0 to 18 years)”

limit 15 to “all adult (19 plus years)”

14 not 15

16 or 17

limit 18 to (english language and humans and yr=“1995 -Current”)