# References

1 Miake-Lye IM, Hempel S, Ganz DA, Shekelle PG. Inpatient fall prevention programs as a patient safety strategy: a systematic review. Annals of internal medicine. 2013;158(5 Pt 2):390–396.23460095
2 Oliver D, Healey F, Haines TP. Preventing falls and fall-related injuries in hospitals. Clin Geriatr Med. 2010;26(4):645–692.20934615
3 Zubkoff L, Neily J, Quigley P, . Virtual Breakthrough Series, Part 2: Improving Fall Prevention Practices in the Veterans Health Administration. Joint Commission journal on quality and patient safety. 2016;42(1553-7250 (Print)):497–ap412.28266918
4 Joint C. Preventing falls and fall-related injuries in health care facilities. Sentinel Event Alert. 2015(55):1–5.
5 Control NCfIPa. Costs of Falls Among Older Adults. Centers for Disease Control and Prevention. https://www.cdc.gov/homeandrecreationalsafety/falls/fallcost.html. Published 2016. Accessed.
6 Quality AfHRa. Preventing Falls in Hospitals. https://www.ahrq.gov/professionals/systems/hospital/fallpxtoolkit/index.html. Published 2018. Updated Jul-Aug. Accessed.
7 Boswell DJ, Ramsey J, Smith MA, Wagers B. The cost-effectiveness of a patient-sitter program in an acute care hospital: a test of the impact of sitters on the incidence of falls and patient satisfaction. Quality management in health care. 2001;10(1):10–16.11702467
8 Manna M. Effectiveness of formal observation in inpatient psychiatry in preventing adverse outcomes: the state of the science. Journal of psychiatric and mental health nursing. 2010;17(3):268–273.20465777
9 Spiva L, Feiner T, Jones D, Hunter D, Petefish J, VanBrackle L. An Evaluation of a Sitter Reduction Program Intervention. Journal of nursing care quality. 2012;27(4):341–345.22692004
10 Laws D, Crawford CL. Alternative strategies to constant patient observation and sitters: a proactive approach. The Journal of nursing administration. 2013;43(1539-0721 (Electronic)):497–501.24061581
11 Pinkhasov A, Singh D, Chavali S, Legrand L, Calixte R. A Proactive Behavioral Health Service Model to Address Use of Constant Observation in a General Hospital. Psychiatric Services. 2018;69(3):251–253.29334881
12 Sterne JA, Hernan MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. BMJ (Clinical research ed). 2016;355:i4919.
13 group Gw. 2014. http://www.gradeworkinggroup.org.
14 Howick J, Glasziou P, Aronson JK. The evolution of evidence hierarchies: what can Bradford Hill’s ‘guidelines for causation’ contribute? J R Soc Med. 2009;102(5):186–194.19417051
15 Giles LC, Bolch D, Rouvray R, . Can volunteer companions prevent falls among inpatients? A feasibility study using a pre-post comparative design. BMC geriatrics. 2006;6:11.16895609
16 Donoghue J, Graham J, Mitten-Lewis S, Murphy M, Gibbs J. A volunteer companion-observer intervention reduces falls on an acute aged care ward. Int J Health Care Qual Assur Inc Leadersh Health Serv. 2005;18(1):24–31.15819122
17 Adams J, Kaplow R. A Sitter-Reduction Program In an Acute Health Care System. Nurs Econ. 2013;31(2):83–89.23691749
18 Bock TJ. Patient Care Sitter Reduction and Fall Safety Improvement. University of San Francisco;2016.
19 Burtson PL, Vento L. Sitter Reduction Through Mobile Video Monitoring A Nurse-Driven Sitter Protocol and Administrative Oversight. Journal of Nursing Administration. 2015;45(7–8):363–369.26133097
20 Cournan M, Fusco-Gessick B, Wright L. Improving Patient Safety Through Video Monitoring. Rehabilitation nursing : the official journal of the Association of Rehabilitation Nurses. 2018;43(2):111–115.29499009
21 Davis J, Kutash M, Whyte IV J. A comparative study of patient sitters with video monitoring versus in-room sitters. Journal of Nursing Education and Practice. 2017;7(3):137–142.
22 Jeffers S, Searcey P, Boyle K, . Centralized video monitoring for patient safety: a Denver Health Lean journey. Nursing economic$. 2013;31(0746-1739 (Print)):298–306.24592534
23 McNicoll L, Cournoyer C, Roach R, . Close Observation Medical Unit: A Model for Nursing and Geriatrics Collaboration. In. Providence, Rhode Island: Alpert Medical School of Brown University; Rhode Island Hospital; 2013.
24 Rausch DL, Bjorklund P. Decreasing the Costs of Constant Observation. Journal of Nursing Administration. 2010;40(2):75–81.20124960
25 Sand-Jecklin K, Johnson JR, Tylka S. Protecting Patient Safety: Can Video Monitoring Prevent Falls in High-Risk Patient Populations? Journal of nursing care quality. 2016;31(1550-5065 (Electronic)):131–138.26513398
26 Skowronsky C, Bena JF, Albert NM. Close Observation Unit to Prevent Falls and Minimize Use of Patient Care Companions. Journal of nursing care quality. 2015;30(1):38–43.24943892
27 Spano-Szekely L, Winkler A, Waters C, . Individualized Fall Prevention Program in an Acute Care Setting: An Evidence-Based Practice Improvement. Journal of nursing care quality. 2018.
28 Tzeng HM, Yin CY, Grunawalt J. Effective assessment of use of sitters by nurses in inpatient care settings. Journal of advanced nursing. 2008;64(2):176–183.18990098
29 Votruba L, Graham B, Wisinski J, Syed A. Video Monitoring to Reduce Falls And Patient Companion Costs For Adult Inpatients. Nursing economic$. 2016;34(0746-1739 (Print)):185–189.29975024
30 Weeks SK. Falls/ambulation: Reducing sitter use: Decision outcomes. Nursing management. 2011;42(12):37–38.
31 Westle M, Burkert G, Paulus R. Reducing Inpatient Falls and Injury Rates by Integrating New Technology with Workflow Redesign. New England Journal of Medicine Catalyst. 2019.
32 Wray K, Rajab-Ali R. Safety Watch Reducing Constant Observation Through Nurse Empowerment and Accountability. Journal of Nursing Administration. 2014;44(4):237–243.24662694