# Acknowledgments

This topic was developed in response to a nomination by Julia Neily, Associate Director, Field Office of the National Center for Patient Safety, and William Gunnar, Executive Director of the National Center for Patient Safety, for the purpose of supporting decisions related to determining whether to add patient sitters or one-to-one observation interventions to a patient safety assessment tool (PSAT) for falls. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors gratefully acknowledge Roberta Shanman, MLS and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend Technical Expert Panel (TEP) participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Julia Neily, RN, MS, MPH
  Associate Director, Field Office
  National Center for Patient Safety
- William Gunnar, MD
  Executive Director
  National Center for Patient Safety

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Christine Engstrom, PhD, CRNP, AOCN, FAANP
  Acting Program Manager, Research & Analytics, Office of Nursing Services
- Tatjana Bulat, MD, CMD
  Director, VISN 8 Patient Safety Center of Inquiry
  Associate Chief of Staff for Geriatrics and Extended Care, James A. Haley VA Hospital and Clinics, Tampa, FL
  Associate Professor of Medicine, Morsani College of Medicine
- David A. Ganz, MD, PhD
  Associate Director, VA HSR&D Center for the Study of Healthcare Innovation, Implementation & Policy, VA Greater LA Healthcare System
  Staff Physician, VA Greater LA Healthcare System, Geriatric Research, Education and Clinical Center (GRECC)
  Associate Professor of Medicine, UCLA

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.