# Summary and Discussion

The key finding of this review is that, despite the strong mechanistic rationale for the use of one-to-one sitters, there is surprisingly little evidence of its effect, with only 2 studies assessing the effect on falls and no studies assessing the effect on wandering or suicide/self-harm. Of the alternatives to sitters that have published results, the use of interventions with video monitoring is the most promising, although like any information technology intervention, the success is likely to be highly context-dependent.

## Summary of Evidence by Key Question

### Key Question 1 What is the effectiveness of patient sitters (one-to-one observation, patient safety companions, etc) for reducing falls?

Regarding the use of sitters added to usual care, there are only 2 observational, time series studies identified, and both also used designated space as part of their intervention. The 2 studies reported conflicting results with regards to change in fall rate, and the baseline rate of falls in these Australian studies was 3 to 4 times that in a typical US acute care hospital.

Regarding alternatives to sitter use, the most evidence was identified for the use of video monitoring, with 8 studies (5 of which used a time series design) reporting mostly consistent results, with either no change or a decrease in falls following implementation, and a dramatic drop in sitter use. Although formal statistical testing was often not performed in these articles, the differences or lack thereof have face validity based on figures presenting the time series data. Most articles reported cost savings in terms of sitter use, but not costs associated with the acquisition of the information technology system, training, and/or maintenance. Two studies of designating space for close observation were difficult to interpret because 1 study had numerous additional co-interventions and the other study was limited by design (pre/post) and lacked precision (clinically significant higher falls risk in the close observation unit, but not statistically significant). Three studies of nurse assessment and decision tools were limited by design (2 studies were pre/post), inconsistent results, and by co-interventions in the single time series study (for example, the observed reduction in use of sitters may have been due to a co-intervention such as the requirement that nursing units report their monthly use of sitter utilization). Among the miscellaneous intervention studies, 1 time series study described a well-planned and well-conducted quality improvement intervention that convincingly shows that a multicomponent intervention tailored to meet local needs and challenges can reduce sitter use while not adversely influencing fall rates.

### Key Question 2 What is the effectiveness of patient sitters (one-to-one observation, patient safety companions, etc) for reducing suicide or self-harm?

We identified no studies reporting the effects of sitters, or alternatives to removing sitters, on the outcomes of suicide or self-harm.

### Key Question 3 What is the effectiveness of patient sitters (one-to-one observation, patient safety companions, etc) for reducing wandering?

We identified no studies reporting the effects of sitters, or alternatives to removing sitters, on the outcome of wandering.

### Key Question 4 What is the cost-effectiveness of one-to-one observations compared to usual care for patients at risk of falls, suicide, or wandering?

We identified no studies reporting the cost-effectiveness of sitters. Many studies of alternatives to sitters reported cost savings due to less use of sitters, and these amounts could be quite substantial, but rarely were the costs of the alternative intervention included in the reporting.

## Limitations

### Publication Bias

Publication bias is a major concern for a topic such as this. Particularly for the “alternatives to sitters” articles, it is highly likely that unsuccessful alternative interventions are less likely to be published. This colors the evidence base for each topic and was considered in our overall rating of the certainty of evidence.

### Study Quality

Study quality is a major concern for this topic. While some of the studies used a time series design sufficient to support causal relationships, most did not. Study quality was considered in our overall rating of the certainty of evidence.

### Heterogeneity

Heterogeneity is a major concern for this topic. Studies’ interventions most often included multiple components, and these were all idiosyncratic—no study tested the same intervention, in all its components, as any other study. We attempted to group study interventions into categories of interventions that shared some similarities, but nevertheless within each category there is still substantial heterogeneity in interventions.

### Applicability of Findings to the VA Population

We did not identify any studies in VA populations. We can only speculate as to the applicability of these findings to VA populations.

## Research Gaps/Future Research

The fundamental value of one-to-one sitters remains a question in search of an answer. Their use may be so ingrained into usual care that a standard randomized control trial comparing sitter use to no sitter use is not feasible to conduct, in which case the “alternatives to sitters” research route should be pursued. This can be done as controlled before-and-after studies within hospital, which will provide a much stronger basis for causal conclusions than a pre/post study, or as a time series study with incremental additions of intervention components.

## Conclusions

The effect of one-to-one sitters on reducing falls, wandering, or suicide/self-harm has yet to be established. Of the alternatives to sitters that have published results, the use of interventions with video monitoring is the most promising, although success is likely to be highly context-dependent.