# Methods

## Topic Development

This topic was developed in response to a nomination by Julia Neily, Associate Director, Field Office for the National Center for Patient Safety and William Gunnar, Executive Director for the National Center for Patient Safety. Key questions were then developed with input from the topic nominator, the ESP coordinating center, the review team, and the technical expert panel (TEP).

The Key Questions were:

- KQ1. What is the effectiveness of patient sitters (one-to-one observation, patient safety companions, etc) for reducing falls?
- KQ2. What is the effectiveness of patient sitters (one-to-one observation, patient safety companions, etc) for reducing suicide or self-harm?
- KQ3. What is the effectiveness of patient sitters (one-to-one observation, patient safety companions, etc) for reducing wandering?
- KQ4. What is the cost-effectiveness of one-to-one observations compared to usual care for patients at risk of falls, suicide, or wandering?

The review was registered in PROSPERO: CRD42019127424.

## Search Strategy

The search strategy, including the search terms and databases used, was created by a reference librarian with more than 25 years of experience performing searches for systematic reviews. We conducted searches in PubMed from inception to 12/18/2018, Web of Science from inception to 11/29/2018, Cochrane Database of Systematic Reviews and Cochrane Trials and PsycINFO from 01/01/1970 to 12/04/2018, and CINAHL from inception to 11/30/2018. The searches used included “sitter,” “patient-sitter,” and “one-to-one observation” as the set of terms. See Appendix A for complete search strategy. We performed a gray literature search on 7/10/19, using Google and the terms “patient sitter effectiveness”. From this search, we reviewed the first 30 hits for studies that would meet eligibility criteria. We also attempted to contact 1 original author for additional detail regarding her study, but she replied that those details of the study were no longer known to her.

## Study Selection

Three team members (AMG, EPT, PGS), working independently, screened the titles of retrieved citations. For titles deemed relevant by at least 1 person, abstracts were then screened independently in triplicate by team members. All disagreements were reconciled through group discussion. Full-text review was conducted in duplicate by 2 independent team members, with any disagreements resolved through discussion. Because we expected few, if any, randomized trials, we did not reject observational studies, and included both time series studies and pre/post studies. In order to be included, a study had to include “one-to-one sitters” (or “specialing,” as it is called in some other countries) or “close observation” unit as an intervention in an acute hospital general medical/surgical or psychiatric hospital setting, and report an outcome of interest (falls, wandering, suicide/self-harm), and report that preventing this outcome was the primary goal of the intervention. Thus, we rejected several studies that were multicomponent interventions that included one-to-one sitters to prevent delirium, and which then also reported falls.^10,11^ We excluded these studies because they are prone to selective outcome reporting bias. We also rejected studies in rehabilitation settings, as the focus of our partner was the acute care hospital setting.

## Data Abstraction

Data extraction was completed in duplicate (AMG/EPT). All discrepancies were resolved with full group discussion. We abstracted data on the following: setting, sample size, study design, use of existing theory/logic model, control/pre-intervention sitter practice, alternative(s) to sitters, implementation details, outcomes, and post-implementation follow-up interval.

## Quality Assessment

We used the Risk of Bias In Non-randomized Studies – of Interventions (ROBINS-I) for observational studies.^12^ This tool requires an assessment of whether a study is at critical, serious, moderate, or low risk of bias (or no information) in 7 domains: confounding, selection bias, bias in measurement classification of interventions, bias due to deviations from intended interventions, bias due to missing data, bias in measurement of outcomes, and bias in selection of the reported result (see Appendix B for tool; Table 1 for ROBINS-I table). Since observational studies are not required to have published an a priori protocol, we operationalized the last domain (bias in selection of the reported result) as requiring that studies report the most common outcomes. We used the latest advice from the Cochrane Methods group on the application of ROBINS-I to time series studies of interventions.

## Data Synthesis

The observational studies were too clinically heterogeneous to support meta-analysis; hence our synthesis is narrative.

## Rating the Body of Evidence

Where possible, a summary of findings and quality of evidence table was used to summarize the existing evidence. We used the principles of the Grading of Recommendations Assessment, Development and Evaluation (GRADE) working group^13^ plus those advocated by Howick and colleagues^14^ to assess the quality of the evidence as follows:

- High: We are very confident that the true effect lies close to that of the estimate of the effect.
- Moderate: We are moderately confident in the effect estimate: The true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.
- Low: Our confidence in the effect estimate is limited: The true effect may be substantially different from the estimate of the effect.
- Very Low/Insufficient: We have very little confidence in the effect estimate: The true effect is likely to be substantially different from the estimate of effect.

## Peer Review

A draft version of the report was reviewed by technical experts. Reviewer comments and our response are documented in Appendix C.