# Introduction

Preventing adverse events in hospitalized patients is a priority goal of patient safety programs. In-facility falls and in-facility suicide are 2 conditions identified as a priority by the technical expert panel involved in the Agency for Healthcare Research and Quality (AHRQ) 2013 report Making Health Care Safer II.^1^ The patient safety practices reviewed in that report included multicomponent interventions to prevent falls, and did not explicitly deal with the use of sitters. Regarding suicide prevention, the report found that “use of staff to observe at-risk patients is frequently employed, but there is no evidence from controlled trials….” The rate of falls in acute-care hospitals is estimated to range from 1.3 to 8.9 per 1,000 patient days, which translates into well over 1,000 falls per year in a large hospital.^2^ The rate of in-facility suicide is not well estimated, but it has been a Joint Commission patient safety goal since 2011. The Joint Commission has previously reported approximately 3% to 20% of inpatients fall at least once during their hospitalization and, in acute and rehabilitation hospitals, injurious falls ranged from 30% to 51% of falls.^3,4^ Falls with serious injury are consistently among the Top 10 sentinel events reported to The Joint Commission’s Sentinel Event database, with a majority of these falls occurring in hospitals. An estimated 700,000 to 1,000,000 hospitalized patients fall each year, and as much as one-third of these falls are considered preventable.^5,6^ The Centers for Disease Control and Prevention (CDC) reported medical costs for falls totaled more than $50 billion in 2015 with evidence suggesting the annual cost is rising, especially with a rising older adult population who have an increased risk of falls with age.^5^ In addition to their direct medical costs, these events cost hospitals an average of $55,000 in legal claims and proceedings and also the potential for revenue loss due to reputational concerns, since fall safety performance is frequently publicly reported.^7^

These adverse events are thought to be preventable to some degree. Nurses or other personnel have been used to monitor patient behavior in continuous or constant observation for more than 35 years^8^ to prevent falls and reduce elopements and suicide/self-harm. The rationale is intuitive and rooted in tradition: with staff immediately at hand to help prevent a fall or redirect a patient from engaging in a harmful act, it has historically been considered proper to utilize the constant observation practice as a protective measure.^8^ But the practice is costly. US acute care hospitals can each spend more than $1 million annually on sitters.^9^

With high costs and uncertain evidence for effectiveness, and even a lack of consensus in the literature about how constant observation should be carried out, our operational partners requested an up-to-date review of sitter use and its impact on patient outcomes, to better inform policy and practice regarding sitter use.