# Executive Summary

## Introduction

Preventing adverse events in hospitalized patients is a priority goal of patient safety programs. In-facility falls and in-facility suicide are 2 priority conditions that are thought to be preventable. One-to-one sitters or constant observation is an intervention that has long been used, rooted in tradition: staff that are immediately at hand can help prevent a fall or redirect a patient from engaging in a harmful act. However, one-to-one sitters is a costly intervention, and evidence that it is effective is uncertain; hence, VA policymakers asked for an up-to-date review to inform policy and practice.

## Methods

### Data Sources and Searches

This topic was developed in response to a nomination by Julia Neily, Associate Director, Field Office for the National Center for Patient Safety and William Gunnar, Executive Director for the National Center for Patient Safety. Key questions were then developed with input from the topic nominator, the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

The Key Questions were:

- KQ1. What is the effectiveness of patient sitters (one-to-one observation, patient safety companions, etc) for reducing falls?
- KQ2. What is the effectiveness of patient sitters (one-to-one observation, patient safety companions, etc) for reducing suicide or self-harm?
- KQ3. What is the effectiveness of patient sitters (one-to-one observation, patient safety companions, etc) for reducing wandering?
- KQ4. What is the cost-effectiveness of one-to-one observations compared to usual care for patients at risk of falls, suicide, or wandering?

### Study Selection

We conducted searches in PubMed from inception to 12/18/2018, Web of Science from inception to 11/29/2018, Cochrane Database of Systematic Reviews and Cochrane Trials and PsycINFO from 01/01/1970 to 12/04/2018, and CINAHL from inception to 11/30/2018. In order to be included, a study had to include one-to-one sitters as an intervention in an acute hospital’s general medical/surgical or psychiatric hospital setting, and report an outcome of interest (falls, wandering, suicide/self-harm), and that preventing this outcome was the primary goal of the intervention. Observational studies were included.

### Data Abstraction and Quality Assessment

Data extraction was completed in duplicate. All discrepancies were resolved with full group discussion. We abstracted data on the following: setting, sample size, study design, use of existing theory/logic model, control/pre-intervention sitter practice, alternative(s) to sitters, implementation details, outcomes, and post-implementation follow-up interval. We used the Risk of Bias In Non-randomized Studies – of Interventions (ROBINS-I) for observational studies to assess study quality/risk of bias.

### Data Synthesis and Analysis

The observational studies were too clinically heterogeneous to support meta-analysis; hence our synthesis is narrative. We used the principles of the Grading of Recommendations Assessment, Development and Evaluation (GRADE) working group to assess the certainty of evidence.

## Results

### Results of Literature Search

We identified 4,106 potentially relevant citations for a total of 1,845 articles whose titles were screened. Nineteen publications were identified at full-text review as meeting initial inclusion criteria. Only 2 studies assessed the effect of adding sitters to a usual care that did not include sitters; both assessed only falls as an outcome. The remaining 17 studies all assessed the effect of interventions aimed at reducing sitter use. All 17 of these studies assessed falls as the outcome of interest. There were no studies that assessed wandering or suicide-related measures as the outcome of interest.

### Summary of Results for Key Questions

#### Key Question 1 What is the effectiveness of patient sitters (one-to-one observation, patient safety companions, etc) for reducing falls?

Regarding the use of sitters added to usual care, there are only 2 observational, time series studies identified, and both also used designated space as part of their intervention. The 2 studies reported conflicting results with regards to change in fall rate, and the baseline rate of falls in these 2 Australian studies was 3 to 4 times that in a typical US acute care hospital.

Regarding alternatives to sitter use, the most evidence was identified for the use of video monitoring, with 8 studies (5 of which used a time series design) reporting mostly consistent results, with either no change or a decrease in falls following implementation, and a dramatic drop in sitter use. Although formal statistical testing was often not performed in these articles, the differences or lack thereof have face validity based on figures presenting the time series data. Most articles reported cost savings in terms of sitter use, but not costs associated with the acquisition of the information technology system, training, and maintenance. Two studies of designating space for close observation were difficult to interpret because 1 study had numerous additional co-interventions and the other study was limited by design (pre/post) and lacked precision (clinically significant higher falls risk in the close observation unit, but not statistically significant). Three studies of nurse assessment and decision tools were limited by design (2 studies were pre/post), inconsistent results, and by co-interventions in the single time series study (for example, the observed reduction in use of sitters may have been due to a co-intervention, such as the requirement that nursing units report their monthly use of sitter utilization). Among the miscellaneous intervention studies, 1 time series study described a well-planned and conducted quality improvement intervention that convincingly shows that a multicomponent intervention tailored to meet local needs and challenges can reduce sitter use while not adversely influencing fall rates.

#### Key Question 2 What is the effectiveness of patient sitters (one-to-one observation, patient safety companions, etc) for reducing suicide or self-harm?

We identified no studies reporting the effects of sitters, or alternatives to removing sitters, on the outcomes of suicide or self-harm.

#### Key Question 3 What is the effectiveness of patient sitters (one-to-one observation, patient safety companions, etc) for reducing wandering?

We identified no studies reporting the effects of sitters, or alternatives to removing sitters, on the outcome of wandering.

#### Key Question 4 What is the cost-effectiveness of one-to-one observations compared to usual care for patients at risk of falls, suicide, or wandering?

We identified no studies reporting the cost-effectiveness of sitters. Many studies of alternatives to sitters reported cost savings due to less use of sitters, and these amounts could be quite substantial, but rarely were the costs of the alternative intervention included in the reporting.

## Discussion

### Key Findings and Strength of Evidence

The key finding of this review is that, despite the strong mechanistic rationale for the use of one-to-one sitters, there is surprisingly little evidence of its effect, with only 2 studies assessing the effect on falls and no studies assessing the effect on wandering or suicide/self-harm. Of the alternatives to sitters that have published results, the use of interventions with video monitoring is the most promising, although like any information technology intervention, the success is likely to be highly context-dependent.

Certainty of Evidence for One-to-One Sitters

Intervention/Outcome | Study Limitations | Consistency | Directness | Precision | Certainty of Evidence
Adding Sitters to Usual Care
Preventing falls | Observational studies: High | Inconsistent | Direct | Imprecise | Very Low
Removing Sitters
Using video monitoring to reduce sitter use and not adversely influence falls | Time Series: Low; Pre/post: High | Consistent | Direct | Imprecise | Moderate
Using designated spaces to reduce sitter use and not adversely influence falls | Time Series: High; Pre/post: High | Inconsistent | Direct | Imprecise | Very Low
Using nurse assessment and decision tools to reduce sitter use and not adversely influence falls | Time Series: Low; Pre/post: High | Inconsistent | Direct | Imprecise | Very Low
Using a multicomponent intervention tailored to meet local needs and challenges to reduce sitter use and not adversely influence falls | Time Series: Low | N/A | Direct | N/A | Low

### Applicability

We did not identify any studies in VA populations. We can only speculate as to the applicability of these findings to VA populations.

### Research Gaps/Future Research

The fundamental value of one-to-one sitters remains a question in search of an answer. Their use may be so ingrained into usual care that a standard randomized control trial comparing sitter use to no sitter use is not feasible to conduct, in which case the “alternatives to sitters” research route should be pursued. This can be done as controlled before-and-after studies within a hospital, which will provide a much stronger basis for causal conclusions than a pre/post study, or as a time series study with incremental additions of intervention components.

### Conclusions

The effect of one-to-one sitters on reducing falls, wandering, or suicide/self-harm has yet to be established. The available data are most compatible with a hypothesis that sitters are at best only modestly effective for fall prevention.

## Abbreviations Table

AHRQ: Agency for Healthcare Research and Quality
CDC: Centers for Disease Control and Prevention
COU: Close Observation Unit
CVM: Continuous Video Monitoring
ESP: Evidence Synthesis Program
GRADE: Grading of Recommendations Assessment, Development and Evaluation
OBD: Occupied Bed Days
PCA: Patient Care Assistant
PSAT: Patient Safety Assessment Tool
ROBINS-I: Risk of Bias in Non-Randomized Studies- of Interventions
ST: Safety Technicians
STRATIFY: St. Thomas Risk Assessment Tool in Falling elderly patients
TEP: Technical Expert Panel
VHA: Veterans Health Administration
VMT: Video Monitor Technician