# APPENDIX D Citations for Excluded Studies

## Background, n=15

1 Patient sitters’ disturbing, firsthand encounters. Hospital Employee Health. 2016;35(4):41–41.
2 Report: Train sitters upon hire, and annually. Hospital Employee Health. 2016;35(4):42.
3 Bailey M, Amato S, Mouhlas C. A creative alternative for providing constant observation on an acute-brain-injury unit. Rehabilitation nursing : the official journal of the Association of Rehabilitation Nurses. 2009;34(1):11–16, 23.19160919
4 Boswell DJ, Ramsey J, Smith MA, Wagers B. The cost-effectiveness of a patient-sitter program in an acute care hospital: a test of the impact of sitters on the incidence of falls and patient satisfaction. Quality management in health care. 2001;10(1):10–16.11702467
5 Feil M, Wallace SC. The Use of Patient Sitters to Reduce Falls: Best Practices. Pennsylvania Patient Safety Advisory. 2014;11(1):8–14.
6 Green JS, Grindel CG. Supervision of suicidal patients in adult inpatient psychiatric units in general hospitals. Psychiatric services (Washington, DC). 1996;47(1075-2730 (Print)):859–863.
7 Laws D, Crawford CL. Alternative strategies to constant patient observation and sitters: a proactive approach. The Journal of nursing administration. 2013;43(1539-0721 (Electronic)):497–501.24061581
8 Lee EA, Gibbs NE, Fahey L, Whiffen TL. Making hospitals safer for older adults: updating quality metrics by understanding hospital-acquired delirium and its link to falls. The Permanente journal. 2013;17(1552-5775 (Electronic)):32–36.24361018
9 Manna M. Effectiveness of formal observation in inpatient psychiatry in preventing adverse outcomes: the state of the science. Journal of psychiatric and mental health nursing. 2010;17(3):268–273.20465777
10 McCurley, J. and J. Pittman (2014). “A new approach to fall prevention in inpatient care implementing remote audio visual monitoring of at risk patients.” Patient Saf Qual Health Care 11(6): 50–53.
11 Pinkhasov A, Singh D, Chavali S, Legrand L, Calixte R. A Proactive Behavioral Health Service Model to Address Use of Constant Observation in a General Hospital. Psychiatric Services. 2018;69(3):251–253.29334881
12 Quigley PA, Votruba L, Kaminski J. Outcomes of Patient-Engaged Video Surveillance on Falls and Other Adverse Events. Clin Geriatr Med. 2019;35(2):253–263.30929886
13 Ray R, Perkins E, Roberts P, Fuller L. The Impact of Nursing Protocols on Continuous Special Observation. Journal of the American Psychiatric Nurses Association. 2017;23(1):19–27.27738084
14 Schoenfisch AL, Pompeii LA, Lipscomb HJ, Smith CD, Upadhyaya M, Dement JM. An Urgent Need to Understand and Address the Safety and Well-Being of Hospital “Sitters”. American journal of industrial medicine. 2015;58(12):1278–1287.26351265
15 Torkelson DJ, Dobal MT. Constant observation in medical-surgical settings: a multihospital study. Nursing economic$. 1999;17(0746-1739 (Print)):149–155.10711154

## Condition, n= 1

1 Esserman L. Recommend Watchful Waiting with Close Observation. In. Vol 374. Waltham, Massachusetts: New England Journal of Medicine; 2016:390–391.

## Duplicate, n=1

1 Burtson PL, Vento L. Sitter Reduction Through Mobile Video Monitoring. Journal of Nursing Administration. 2015;45(7/8):363–369.26133097

## Intervention, n=4

1 Chan DK, Sherrington C, Naganathan V, . Key issues to consider and innovative ideas on fall prevention in the geriatric department of a teaching hospital. Australasian journal on ageing. 2018;37(2):140–143.29679434
2 Schoenfisch A, Pompeii L, Lipscomb H, Dement J. Violence perpetrated by hospital patients and visitors (type II) against ‘sitters’. Occupational & Environmental Medicine. 2014;71:A53–A53.
3 Shever LL, Titler MG, Mackin ML, Kueny A. Fall prevention practices in adult medicalsurgical nursing units described by nurse managers. Western journal of nursing research. 2011;33(3):385–397.20921126
4 Zubkoff L, Neily J, Quigley P, . Virtual Breakthrough Series, Part 2: Improving Fall Prevention Practices in the Veterans Health Administration. Joint Commission journal on quality and patient safety. 2016;42(1553-7250 (Print)):497–ap412.28266918

## Letter, n=2

1 Melear B. Support for sitter alternatives…‘A S.A.F.E. alternative to sitters’, Nurs Manage, 2009 August issue. Nursing management. 2009;40(12):8–8.
2 Routh A, Sustaita L, Pamperin R, Holguin M. Cost containment detrimentally affects patient care… ‘Constant observation: implications for nursing practice’. Journal of Psychosocial Nursing & Mental Health Services. 1995;33(8):3–3.

## Outcome, n=12

1 Carr FM. The role of sitters in delirium: an update. Canadian geriatrics journal : CGJ. 2013;16(1):22–36.23440038
2 DeSousa, T. L. (2011). Evaluation of the Patient Sitter Assessment Tool. [underlined: Nursing], Rhode Island College. Master of Science in Nursing (MSN).
3 McNicoll L, Baumhover L, Gifford D, Inouye S. Impact Of ‘Sitter’ Reduction Policies On Restraint Use; The Effect Of A Targeted Multicomponent Intervention In. Providence, Rhode Island: Rhode Island Hospital; 2018.
4 Moghabghab R. Constant Observation for Older Adults in Acute Care: A Mixed Methods Study. Constant Observation for Older Adults in Acute Care: Mixed Methods Study. 2017:1–1.
5 Moore V, Allen L, Nash MG, Buck J, Chipps E. Exploring Nurses’ Perception of Dynamic Patient Events. The Journal of nursing administration. 2016;46(2):57–60.26796818
6 Moyle W, Borbasi S, Wallis M, Olorenshaw R, Gracia N. Acute care management of older people with dementia: a qualitative perspective. Journal of clinical nursing. 2011;20(3–4):420–428.21029231
7 Nadler-Moodie M, Burnell L, Fries J, Agan DL. A S.A.F.E. alternative to sitters…Specialized Adult-Focused Environment. Nursing management. 2009;40(8):43–50.
8 Richman C, Sarnese P. Patient Sitter Use Within Hospitals: A Cross-Sectional Study. International Healthcare Security and Safety Foundation;2014.
9 Riddell K. A comparative study of the constant observation model of care, Master of Nursing thesis: School of Nursing and Midwifery, Deakin University; 2012.
10 Siddharthan K, Nelson A, Tiesman H, Chen FF. Advances in Patient Safety Cost-effectiveness of a Multifaceted Program for Safe Patient Handling. In: Henriksen K, Battles JB, Marks ES, Lewin DI, eds. Advances in Patient Safety: From Research to Implementation (Volume 3: Implementation Issues). Rockville (MD): Agency for Healthcare Research and Quality (US); 2005.
11 Tzeng H, Yin C. International perspectives. Using family visitors, sitters, or volunteers to prevent inpatient falls. Journal of Nursing Administration. 2007;37(7/8):329–334.17939463
12 Wilkes L, Jackson D, Mohan S, Wallis M. Close observation by ‘specials’ to promote the safety of the older person with behavioural disturbances in the acute care setting. Contemporary nurse. 2010;36(1037-6178 (Print)):131–142.21254829

## Systematic Review, n=4

1 Lang CE. Do sitters prevent falls? A review of the literature. Journal of gerontological nursing. 2014;40(5):24–33; quiz 34–25.
2 Nienaber A, Schulz M, Hemkendreis B, Lohr M. Special Observation in Inpatient Treatment of People with Mental Illness A Systematic Review of the Literature. Psychiatr Prax. 2013;40(1):14–20.23319278
3 Wood VJ, Vindrola-Padros C, Swart N, . One to one specialling and sitters in acute care hospitals: A scoping review. International journal of nursing studies. 2018;84:61–77.29772447
4 Xu C, Audrey TX, Shi SL, . Effectiveness of interventions for the assessment and prevention of falls in adult psychiatric patients: A systematic review. JBI library of systematic reviews. 2012;10(9):513–573.27820546

## Unavailable, n=13

1 Patient sitters found effective in reducing falls. Healthcare Risk Management. 2014;36(6):54–55.
2 Six elements key to patient sitter program. Healthcare Risk Management. 2014;36(6):55–56.
3 Sitter inattention still can let falls happen. Healthcare Risk Management. 2014;36(6):56–56.
4 Video monitoring reduces falls as well as cutting costs for hospitals. Healthcare Risk Management. 2015;37(7):79–80.
5 Fall-risk patients monitored continuously by video. Healthcare Risk Management. 2015;37(7):80–80.
6 ‘More than a sitter’: a practice development project on special observation in acute general hospital care. Foundation of Nursing Studies: Improvement Insights. 2017;12(1–10):3–3.
7 Alspach G. Where are we heading in healthcare?…patients’ basic needs for physical care and safety met by hired sitters rather than staff nurses. Critical care nurse. 2001;21(2):11–14.11858433
8 Dennis S. Formal observation in the acute in-patient setting: policy, training and practice. Mental Health Care. 1998;2(1):26–28.
9 Evans G. Patient ‘sitters’ at high risk of violence, physical threats. Hospital Employee Health. 2016;35(4):37–40.
10 Fielden NM. Managers forum. Video monitoring of psychiatric patients. JEN: Journal of Emergency Nursing. 2003;29(3):276–277.
11 Kramer JR, Mittlestedt D. ‘Geriatric sitter’ provides needed attention for difficult patients. Modern Nursing Home. 1971;26:44–45.5204896
12 Lipkis-Orlando R, Mian P, Levy G, Lussier-Cushing M. Challenge for the 90s: a safe and cost-effective sitter program… patients who are suicidal, confused, and display unpredictable behavior. MEDSURG Nursing. 1993;2(6):483–485.8261002
13 Sandrick K. Clear policies are needed to guide the use of ‘hired sitters’ in acute care. COR Clinical Excellence. 2001;2(4):4–5.