# APPENDIX C Peer Review Comments/Author Responses

Question | Reviewer comment | Authors’ response
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | Yes - Unclear. Authors did not search SCOPUS, EMBASE, or search for gray literature. | See below for a detailed discussion of our search strategy.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | Yes - I realize this one may have come out after you did your search.; Sand-Jecklin . Video Monitoring for Fall Prevention and Patient Safety 2018 J Nurs Care Qual Vol 34 No. 2 pp145–150; Would like to understand why excluded for background, thank you. Quigley . Outcomes of Patient-Engaged Video Surveillance on Falls and Other Adverse Events. Clin Geriatr Med 35 (2019) 253–263 30929886 | The paper by Sand-Jecklin (2018) was about outcomes rather than falls, and hence we could not include it. We did include as evidence the earlier paper by Sand-Jecklin (2016).; The paper by Quigley and colleagues could not be included as evidence as it did not report any pre-intervention data points; it was thus excluded.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Excellent report addressing the request | Thank you for your comment.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | I have added comments in the manuscript using the notes. | Thank you for your comments. We have read the attached document and incorporated the comments in this table.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Great job!!! No comments except would like to edit my info listed under Technical Expert Panel to read:; Tatjana Bulat, MD,CMD; Director, VISN 8 Patient Safety Center of Inquiry; Associate Chief of Staff for Geriatrics and Extended Care, James A. Haley VA Hospital and Clinics, Tampa, FL; Associate Professor of Medicine, Morsani College of Medicine | Thank you for your comments. We have now made these changes to the text.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | General comments: this report serves a very useful purpose in synthesizing the evidence to date on safety attendants and related interventions for the prevention of falls. The report was well-written. | Thank you for your comment.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | The interventions focused on video monitoring seem relevant to the VA, but the business case does not seem fully established by the publications reviewed, in part because the cost of acquiring the video technology was not always factored into the cost calculations, if I understood correctly.; Did any of the articles comment on sustainability of the video interventions? It would seem likely that if there was a true business case for the video intervention (i.e., if it truly paid for itself) and stakeholders perceived clinical value, then the intervention would be likely to be sustained. | This is a great question. A few of the video monitoring studies noted things like ROI or reported that the hospital administration had scaled up the intervention, which implies that leadership judged the costs to be worth the benefit. We added text to those studies.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Page 1, line 12 - delete “can” from “help can prevent” | We re-phrased this to “staff…at hand can help prevent a fall”
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Page 6, lines 43–44 - It is noted that “US acute care hospitals can spend more than $1 million annually on sitters” - is this the cost per hospital (more plausible) or the cost across all US acute care hospitals combined? | It is the cost-per-hospital. We rephrased this to make it clearer.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Page 9, line 30 - It’s written that “…the data presented here are all from observational studies.” This confused me when I first read it, because when I hear the term “observational study,” it makes me think that no intervention was conducted, i.e., a cohort study where the people with sitters and without sitters were followed to observe their fall rates.; Consider defining the term “observational studies” or using an alternative like “non-randomized intervention studies” or “quasi-experimental studies.” | We changed this to “observational studies, primarily time series analyses of the effect of an intervention.”
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Page 9, line 52–53 - another potential issue related to bias in outcome ascertainment is that the individuals collecting the data on falls may or may not have been blinded to the interventions that were ongoing. | We have added this to the list of issues.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Table 2 (intervention components) - found this table to be a useful compilation of the interventions that have been tried in the literature to date. | Thank you for your comment.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Page 14, line 56 - p values is reported as “p<0.000” - is this a typo or is it how the study reported it? P value must be a positive number. | That is how it is reported in the original article. We presume that what the authors mean is that it is a positive number, but even smaller than 0.000 (for example, 0.0001).
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Page 14, line 58 - should be “percent of patients” rather than “number of patients” | Thank you for your comments. We have now made these changes to the text.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Page 18, line 11 - what does “an indicated cost savings” mean? Did they give a number or just qualitatively report that there was cost savings? | We took out the “indicated”, so it is just “a cost savings was reported”.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Page 19, line 35 - is “Donoghue and Giles” referring to a single study by those two authors or to two separate studies, one by Donoghue and one by Giles? | These are two different studies; we have re-phrased to make that clear.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Thank you for the opportunity to review this report. This is an important issue, but unfortunately the authors have displayed that the currently available literature does not provide adequate guidance to improve decision making. I reviewed this report with the attached PRISMA checklist. There appear to be a couple of issues that could be clarified/improved in items 11–15 and 17. Please see attached comments. Cleaning up these issues may help others avoid the compulsion to spend their time repeating this work. Thanks again for your contribution. | Thank you for your comment. See responses to individual comments, below.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Thank you so much for doing this important review. This issue is critically important since falls can cause loss of function and loss of life. Sitters use many resources and we are not even sure they help. This could also be helpful for families who may wonder why their loved one didn’t get one to one observation. | Thank you for your comment.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | This is my error for not noticing sooner: KQ1: ideally this would address the effectiveness of reducing falls and fall-related injuries. I see that when possible you mentioned outcomes that measured falls with injury. I think it would be worth it to state this in KQ1 and whenever possible state the impact on fall-related injuries. I realize there is probably not much more on this but just to close the loop on this would be valuable. | We specifically looked for and abstracted when it was present the outcome of fall was with injury. Unfortunately, this was not common, as most articles reported only falls.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Study selection: My error for not noticing sooner but the papers were pulled from acute care only. So much of VA falls are in CLC- could you also look at papers from long term care?; I realize there may not be more literature addressing long term care settings for falls but also important to let readers know you looked for this. | The limitation of the eligible settings to acute care only was made very early in this process, and we can’t go back and easily retrieve the long-term care articles, as they would have been rejected and included in the 1,700+ rejects. If evidence on sitters and alternatives to sitters is desired, we suggest nominating it to the ESP as a new topic.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Excellent introduction, well referenced and covered important points about falls. | Thank you for your comment.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Pg 4, Lines 29–30: poor grammar here, don’t end the sentence with “at”…. | Thank you for your comment. We have now made this change to the text.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Pg 6, Line 44: Is that the total cost for the US for one year or in one hospital for one year? It seems very low if it is the US. | This is the cost-per-hospital. Re-phrased to make this clear.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Pg 8, Line 28: Do you have a reference for this? | This information was given to us via email directly from Jo McKenzie, who said it was a pre-print of Chapter 25 in the 2019 edition of the Cochrane Handbook. Not sure if it is publicly available yet, but we are sure it is the latest advice.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Pg 17, Lines 55–59: This is confusing, I thought there WAS a significant difference from pre to post intervention?? | It was confusing as written. The statistically significant difference was between the pre-intervention period and the post-intervention period for patients in the brain injury unit. The nonsignificant difference was within the brain injury unit post-intervention, comparing patients who were placed in the video monitored rooms as compared to other patients. Changes made to the text to clarify.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Pg 18, Lines 19–21: Is this decrease for the video group vs. the non-video group for all groups over time? | Yes, that is correct—it is 9 months of pre-intervention data across all 3 units compared with 9 months of post-intervention data. Text added to clarify this.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Pg 19, Line 37: I’m not sure where these other studies are discussed - you mean you have already discussed them or they will be discussed below? | They were presented earlier in the “Adding Sitters to Prevent Falls” section. Text added to guide readers to this.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Pg 27, Line 48–49: We can only speculate as to the applicability of these finding to VA populations. | Thank you for your comment. We have now made this change to the text.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Appendix E: Evidence Table - this table is very hard to read, can you present the data in another way e.g. as a bulleted paragraph with sub-headings? | It’s a challenge, for sure. We tried some other formats, none of which seemed ideal, and this format is what we thought was the best balance between detail and presentation.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Data items: A full description of measures seems limited/lacking—what is the “outcome” they are looking to see change/improve? | We’re not sure what part of text this is referring to. Almost all the studies were seeking to decrease the number of hours sitters were ordered to prevent falls, so the outcomes were sitter use, measured in hours or money, and falls, either falls in general or falls with injury.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Risk of bias in individual studies: Additional use of GRADE seems fine, though a bit confusing because all they had was a narrative synthesis. Could the authors be more clear about what they mean about effect estimate when they didn’t do a meta-analysis? Need to be clear on how they were collating the data so the reviewer understands how they were comparing studies across one another to determine “improvement” “worsening” or “no change” | The only GRADE criteria that is different across the interventions and outcomes assessed is that video monitoring reduced sitter use while not adversely influencing falls, which was judged as having consistent evidence, because all studies reported these outcomes, whether statistically tested or not.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | The search for articles (if the authors are attempting to comment as strongly as they are on publication bias) is insufficient. There appears to be handwaving when referring to publication bias as the authors do not provide quantitative evidence. They do not mention reviewing the references of included studies or searching a formal trial registry such as clinicaltrials.gov or looking at conference abstracts. They also did not search a more comprehensive database such as EMBASE or SCOPUS.; There is no mention on involving a reference librarian. It is unclear whether they limited to English only studies. That being said, their searches were reasonable but given that they only found 16 references. To be thorough suggests the authors should consider searching SCOPUS or EMBASE and make some attempt to find grey literature. | We understand the reviewer’s desire for more or different databases to be searched, but this type of critique can be applied to every review of every topic – there are far more databases that can be searched than there is time and money to search them. Choices have to be made. We made our choices based on the input of our reference librarian, Roberta Shanman, MLS, who is listed in the acknowledgement (but we will now include this information in the Methods, too, since it may be overlooked in the acknowledgments). We did not search SCOPUS because it is our experience that SCOPUS has content similar to Web of Science, which we did search. We did not search EMBASE because this is not the type of intervention for which EMBASE has a known added benefit to searching PubMed (for example, EMBASE lists RCTs of drug interventions that are not found in PubMed).; Instead, given this intervention, we searched CINAHL, with its focus on nurses and other health professionals. We did search the references of included studies (see next comment). We did not search clinicaltrials.gov, as we did not find a single included study that reported it to have been prospectively registered, indicating to us that studies of these interventions are not viewed by their investigators as something needing or requiring prospective registration. The gray literature search suggestion is a good one, and for this revision we did a gray literature search. We found 3 additional studies, which are now included – but the addition of these studies does not change any conclusion. We disagree with our presentation of the possibility of publication bias as handwaving. Firstly, we are not able to do statistical testing for unexplained heterogeneity, due to the nature of the data. Secondly, we are describing the real world of quality improvement initiatives, in that most – both successful and unsuccessful – almost certainly never get written up for publication. Virtually every US hospital is engaged each year in 1 or more QI initiatives, and there are nowhere near that number of QI publications from US hospitals each year.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Please explain “Ref mine:10.” Is this a review of reference lists? | Ref mine is a review of reference lists.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | It might be better to have Table 1 present study characteristics for which data were extracted (e.g., study size, PICOS, follow-up period)/provide the citations and make the Robins table a later table. | The evidence table with the PICOS, study design, sample size, etc., is by ESP format something that is placed in the Appendix, so we did not move it into the body of the report (it is 40+ pages long).