# APPENDIX A Search Strategies

PATIENT SITTERS

SEARCH METHODOLOGY

DATABASE SEARCHED & TIME PERIOD COVERED:

Web of Science – From inception to 11/29/2018

LANGUAGE:

English

SEARCH STRATEGY:

“FORWARD SEARCHES” ON THE FOLLOWING ARTICLES:

- Boswell, D. J., J. Ramsey, M. A. Smith and B. Wagers. (2001) “The cost-effectiveness of a patient-sitter program in an acute care hospital: a test of the impact of sitters on the incidence of falls and patient satisfaction.” [underlined: Qual Manag Health Care] 10(1): 10–6.11702467
- Carr, F. M. “The role of sitters in delirium: an update.” (2013) [underlined: Can Geriatr J] 16(1): 22–36.23440038
- Chu S. Special observations in the care of psychiatric inpatients: A review of the literature and developments in practice. (2016) ARC Journal of Psychiatry. 1(1):21–31.
- Cox, A., M. Hayter and J. Ruane. “Alternative approaches to ‘enhanced observations’ in acute inpatient mental health care: a review of the literature.” (2010) [underlined: J Psychiatr Ment Health Nurs] 17(2): 162–71.20465762
- Feil M, Wallace S. The use of patient sitters to reduce falls: Best practices. (2014) Pennsylvania Patient Safety Advisory. 11(1):8–14.
- Lang, C. E. “Do sitters prevent falls? A review of the literature.” (2014) [underlined: J Gerontol Nurs] 40(5): 24–33; quiz 34–5.
- Manna, M. “Effectiveness of formal observation in inpatient psychiatry in preventing adverse outcomes: the state of the science.” (2010) [underlined: J Psychiatr Ment Health Nurs] 17(3): 268–73.20465777
- Muralidharan, S. and M. Fenton. “Containment strategies for people with serious mental illness.” (2006) [underlined: Cochrane Database Syst Rev](3): Cd002084.16855984
- Salamon, L. and M. Lennon. “Decreasing companion usage without negatively affecting patient outcomes: a performance improvement project.” (2003) [underlined: Medsurg Nurs] 12(4): 230–6; quiz 237.14515602
- Xu, C., T. X. Audrey, S. L. Shi, Y. W. Shanel, J. M. Tan, K. Premarani, R. Parasuram and S. V. Kumar. “Effectiveness of interventions for the assessment and prevention of falls in adult psychiatric patients: A systematic review.” (2012) [underlined: JBI Libr Syst Rev] 10(9): 513–573.27820546

----------------------------------------------------------------------------------------

DATABASE SEARCHED & TIME PERIOD COVERED:

PubMed – From inception to 12/18/2018

LANGUAGE:

English

SEARCH STRATEGY:

sitter*[tiab] OR sitter*[ot] OR patient-sitter* OR “enhanced observation” OR “formal observation” OR “continuous observation” OR “constant observation” OR “special observation” OR one-to-one observation* OR “close observation” OR patient observ* OR “patient safety assistant” OR “patient safety assistants” OR patient attendant* OR liaison nurse* OR ((virtual observ* OR video observ* OR video monitor* OR remote observ*) AND (patient OR patients)) OR “patient companion” OR “patient companions”

AND

safety management[mh] OR safety[mh] OR patient safety[mh] OR patient satisfaction[mh] OR accidental falls[mh] OR risk management[mh] OR suicide,attempted[mh] OR mental disorders[mh] OR crisis intervention[mh] OR self-injurious behavior[mh] OR violence[mh] OR nursing care[mh] OR wandering behavior[mh] OR accident prevention[mh] OR safe[tiab] OR safe[ot] OR safety[tiab] OR safety[ot] OR fall[tiab] OR fall[ot] OR falls[tiab] OR falls[ot] OR falling[tiab] OR falling[ot] OR wander*[tiab] OR wander[ot] OR suicid*[tiab] OR suicid*[ot] OR accident*[tiab] OR accident*[ot] OR self-harm*[tiab] OR self-harm*[ot] OR self harm*[tiab] OR self harm*[ot]

AND

cost-benefit analysis OR cost OR costs OR costly OR cost effective OR finance OR financial OR expense* OR expensive OR economic OR expenditure* OR effective OR effectiveness OR ineffective OR inefficient OR benefit* OR burden* OR intrusive OR deleterious OR reduction OR reduce OR reducing

----------------------------------------------------------------------------------------

DATABASE SEARCHED & TIME PERIOD COVERED:

CINAHL – From inception to 11/30/2018

LANGUAGE:

English

SEARCH STRATEGY #1:

TI ( sitter* OR patient-sitter* OR “enhanced observation” OR “formal observation” OR “continuous observation” OR “constant observation” OR “special observation” OR “one-to-one observation” OR “close observation” OR “patient safety assistant” OR “patient safety assistants” OR “patient attendant” OR “patient attendants”) OR AB ( sitter* OR patient-sitter* OR “enhanced observation” OR “formal observation” OR “continuous observation” OR “constant observation” OR “special observation” OR “one-to-one observation” OR “close observation” OR “patient safety assistant” OR “patient safety assistants” OR “patient attendant” OR “patient attendants”) OR TI ( (virtual OR video OR remote*) AND (observ* OR monitor*) AND (patient OR patients) ) OR AB ( (virtual OR video OR remote*) AND (observ* OR monitor*) AND (patient OR patients) )

AND

MH “Injuries, Self-Inflicted/PC” OR “accident prevention” OR MH “Accidents” OR

MH “Suicide, Attempted” OR MH “Behavioral Symptoms” OR MH “Suicidal Ideation” OR

MH “Accidental Falls” OR MH “Patient Safety+”

NOT

cardio OR heart OR defibrill* OR cardiac OR diabetes OR fibrill*

SEARCH STRATEGY #2:

TI (sitter* OR patient-sitter* OR “enhanced observation” OR “formal observation” OR “continuous observation” OR “constant observation” OR “special observation” OR “one-to-one observation” OR “close observation”) OR TI (“patient safety assistant” OR “patient safety assistants” OR “patient attendant” OR “patient attendants” ) OR TI ( (virtual OR video OR remote*) AND (observ* OR monitor*) AND (patient OR patients) )

NOT

cardio OR heart OR defibrill* OR cardiac OR diabetes OR fibrill*

=====================================================================

DATABASE SEARCHED & TIME PERIOD COVERED:

Cochrane Database of Systematic Reviews and Cochrane Trials – 1/1/1970 to 12/4/2018

LANGUAGE:

English

SEARCH STRATEGY:

sitter* OR patient-sitter* OR “enhanced observation” OR “formal observation” OR “continuous observation” OR “constant observation” OR “special observation” OR “one-to-one observation” OR “close observation”):ti,ab,kw (Word variations have been searched

OR

[ (“patient safety assistant” OR “patient safety assistants” OR (patient attendant” OR “patient attendants”) OR (virtual OR video OR remote*) AND (observ* OR monitor*) AND (patient OR patients)):ti,ab,kw(Word variations have been searched)

AND

MeSH descriptor: [Patient Safety] explode all trees OR MeSH Descriptor: [Patient Harm] explode all trees OR MeSH descriptor: [Safety Management] explode all trees OR MeSH descriptor: [Accident Prevention] explode all trees OR MeSH descriptor: [Accidental Falls] explode all trees OR MeSH descriptor: [Accidents] this term only OR MeSH descriptor: [Suicidal Ideation] explode all trees OR MeSH descriptor: [Suicide, Attempted] explode all trees OR MeSH descriptor: [Suicide] this term only OR MeSH descriptor: [Self-Injurious Behavior] explode all trees ]

=====================================================================

DATABASE SEARCHED & TIME PERIOD COVERED:

PsycINFO – 1/1/1970 to 12/4/2018

LANGUAGE:

English

SEARCH STRATEGY:

TI (sitter* OR patient-sitter* OR “enhanced observation” OR “formal observation” OR “continuous observation” OR “constant observation” OR “special observation” OR “one-to-one observation” OR “close observation” ) OR AB (sitter* OR patient-sitter* OR “enhanced observation” OR “formal observation” OR “continuous observation” OR “constant observation” OR “special observation” OR “one-to-one observation” OR “close observation” ) OR TI “patient safety assistant” OR “patient safety assistants” OR “patient attendant” OR “patient attendants” ) OR AB (“patient safety assistant” OR “patient safety assistants” OR “patient attendant” OR “patient attendants” )

OR

[ TI ((virtual OR video OR remote*) AND (observ* OR monitor*) AND (patient OR patients) ) OR SU ( ( virtual OR video OR remote*) AND (observ* OR monitor*) AND (patient OR patients) ) OR AB ( ( virtual OR video OR remote*) AND (observ* OR monitor*) AND (patient OR patients) ) )

AND

DE “Patient Safety” OR DE “Falls” OR DE “Accident Prevention” OR DE “Self-Injurious Behavior” OR DE “Self-Destructive Behavior” OR DE “Head Banging” OR DE “Self-Inflicted Wounds” OR DE “Self-Mutilation” OR DE “Attempted Suicide” ]