# REFERENCES

1 Aigbogun MS, Stellhorn R, Hartry A, . Treatment patterns and burden of behavioral disturbances in patients with dementia in the United States: a claims database analysis. BMC Neurol. 2019;19(1):33.30819136
2 Khandker RK, Chekani F, Mirchandani K, . Economic outcomes associated with diagnosed behavioral symptoms among patients with dementia in the United States: a health care claims database analysis. BMC Geriatr. 2023;23(1):99.36797678
3 Kales HC, Gitlin LN, Lyketsos CG. Assessment and management of behavioral and psychological symptoms of dementia. BMJ (Online). 2015;350.
4 Lyketsos CG, Lopez O, Jones B, . Prevalence of Neuropsychiatric Symptoms in Dementia and Mild Cognitive Impairment: Results From the Cardiovascular Health Study. JAMA. 2002;288(12):1475–1483.12243634
5 McCarthy JF, Blow FC, Kales HC. Disruptive behaviors in Veterans Affairs nursing home residents: how different are residents with serious mental illness? J Am Geriatr Soc. 2004;52(12):2031–8.15571538
6 McGarry BE, Joyce NR, McGuire TG, . Association between High Proportions of Seriously Mentally Ill Nursing Home Residents and the Quality of Resident Care. J Am Geriatr Soc. 2019;67(11):2346–2352.31355443
7 Tay FHE, Thompson CL, Nieh CM, . Person-centered care for older people with dementia in the acute hospital. Alzheimers Dement (N Y). 2018;4:19–27.29955648
8 Molinari VA, Merritt SS, Mills WL, . Serious mental illness in Florida nursing homes: need for training. Gerontology & Geriatrics Education. 2008;29(1):66–83.19042228
9 van Duinen-van den IJssel JCL, Mulders A, Smalbrugge M, . Nursing Staff Distress Associated With Neuropsychiatric Symptoms in Young-Onset Dementia and Late-Onset Dementia. J Am Med Dir Assoc. 2018;19(7):627–632.29146222
10 Alzheimer’s Association. Dementia Care Practice Recommendations: Supplemental issue of The Gerontologist. Available at: https://www.alz.org/media/Documents/alzheimers-dementia-care-practice-recommendations.pdf. Accessed September 6, 2023.
11 Bonner AF, Field TS, Lemay CA, . Rationales that providers and family members cited for the use of antipsychotic medications in nursing home residents with dementia. J Am Geriatr Soc. 2015;63(2):302–308.25643635
12 Crystal S, Jarrín OF, Rosenthal M, . National Partnership to Improve Dementia Care in Nursing Homes Campaign: State and Facility Strategies, Impact, and Antipsychotic Reduction Outcomes. Innovation in Aging. 2020;4(3).
13 U.S. Department of Health and Human Services. Long-Term Trends of Psychotropic Drug Use in Nursing Homes. 2022. Available at: https://oig.hhs.gov/oei/reports/OEI-07-20-00500.asp?hero=psychotropic-nursing-home-hero. Accessed September 6, 2023.
14 Maher AR, Maglione M, Bagley S, . Efficacy and comparative effectiveness of atypical antipsychotic medications for off-label uses in adults: a systematic review and meta-analysis. JAMA. 2011;306(12):1359–69.21954480
15 U.S. Food and Drug Administration. FDA Public Health Advisory Deaths with Antipsychotics in Elderly Patients with Behavioral Disturbances. Available at: https://psychrights.org/drugs/FDAantipsychotics4elderlywarning.htm. Accessed September 6, 2023.
16 Wang WW, Moyle W. Physical restraint use on people with dementia: a review of the literature. Aust J Adv Nurs. 2005;22(4):46–52.16496836
17 Pu L, Moyle W. Restraint use in residents with dementia living in residential aged care facilities: A scoping review. J Clin Nurs. 2022;31(13–14):2008–2023.32890437
18 Alzheimer’s Association. Falls, Wandering, and Physical Restraints: Interventions for Residents with Dementia in Assisted Living and Nursing Homes. 2006. Available at: https://www.alz.org/national/documents/fallsrestraints_litereview_ii.pdf. Accessed September 6, 2023.
19 Alzheimer’s Association. ASSISTED LIVING POLICY RECOMMENDATIONS. Available at: https://www.alz.org/national/documents/assisted_living_recomm.pdf. Accessed September 6, 2023.
20 The Joint Commission. Memory Care Fact Sheet. Available at: https://www.jointcommission.org/resources/news-and-multimedia/fact-sheets/facts-about-memory-care/. Accessed September 6, 2023.
21 Karlin BE, Visnic S, Shealy McGee J, . Results from the multisite implementation of STAR-VA: A multicomponent psychosocial intervention for managing challenging dementia-related behaviors of veterans. Psychological Services. 2014;11(2):200–208.23937081
22 Ne’eman A, Stein M, Grabowski DC. Nursing Home Residents Younger Than Age Sixty-Five Are Unique And Would Benefit From Targeted Policy Making. Health Aff (Millwood). 2022;41(10):1449–1459.36190884
23 Bartels SJ, Levine KJ, Shea D. Community-based long-term care for older persons with severe and persistent mental illness in an era of managed care. Psychiatr Serv. 1999;50(9):1189–97.10478906
24 Fashaw SA, Thomas KS, McCreedy E, . Thirty-Year Trends in Nursing Home Composition and Quality Since the Passage of the Omnibus Reconciliation Act. J Am Med Dir Assoc. 2020;21(2):233–239.31451383
25 Jutkowitz E, Brasure M, Fuchs E, . Care-delivery interventions to manage agitation and aggression in dementia nursing home and assisted living residents: A systematic review and meta-analysis. J Am Geriatr Soc. 2016;64(3):477–488.27000321
26 Lewin S, Hendry M, Chandler J, . Assessing the complexity of interventions within systematic reviews: development, content and use of a new tool (iCAT_SR). BMC Medical Research Methodology. 2017;17(1):76.28446138
27 Fazio S, Pace D, Maslow K, . Alzheimer’s Association Dementia Care Practice Recommendations. The Gerontologist. 2018;58(suppl_1):S1–S9.29361074
28 RoB 2: A revised Cochrane risk-of-bias tool for randomized trials Available at: https://methods.cochrane.org/bias/resources/rob-2-revised-cochrane-risk-bias-tool-randomized-trials. Accessed September 11, 2023.
29 ROBINS-I: Risk Of Bias In Non-Randomized Studies of Interventions. Available at: https://methods.cochrane.org/bias/risk-bias-non-randomized-studies-interventions. Accessed September 11, 2023.
30 White IR, Thomas J. Standardized mean differences in individually-randomized and cluster-randomized trials, with applications to meta-analysis. Clin Trials. 2005;2(2):141–51.16279136
31 metafor. Meta-analysis package for R. Version 4.2-0. The Comprehensive R Archive Network; 2023. Available at: https://wviechtb.github.io/metafor/index.html. Accessed October 27, 2023.
32 Guyatt G, Oxman AD, Akl EA, . GRADE guidelines: 1. Introduction-GRADE evidence profiles and summary of findings tables. J Clin Epidemiol. 2011;64(4):383–94.21195583
33 Klapwijk MS, Caljouw MAA, Pieper MJC, . Change in quality of life after a multidisciplinary intervention for people with dementia: A cluster randomized controlled trial. International Journal of Geriatric Psychiatry. 2018;11:11.
34 Stensvik GT, Helvik AS, Haugan G, . The short-term effect of a modified comprehensive geriatric assessment and regularly case conferencing on neuropsychiatric symptoms in nursing homes: a cluster randomized trial. BMC Geriatrics. 2022;22(1):316.35410145
35 Galik EM, Resnick B, Holmes SD, . A Cluster Randomized Controlled Trial Testing the Impact of Function and Behavior Focused Care for Nursing Home Residents With Dementia. J Am Med Dir Assoc. 2021;22(7):1421–1428.e4.33454311
36 Resnick B, Boltz M, Galik E, . Testing the Impact of FFC-AL-EIT on Psychosocial and Behavioral Outcomes in Assisted Living. J Am Geriatr Soc. 2021;69(2):459–466.33095469
37 Kirkham J, Maxwell C, Velkers C, . Optimizing Prescribing of Antipsychotics in Long-Term Care (OPAL): A Stepped-Wedge Trial. J Am Med Dir Assoc. 2020;21(3):381–387.e3.31558380
38 Livingston G, Barber J, Marston L, . Clinical and cost-effectiveness of the Managing Agitation and Raising Quality of Life (MARQUE) intervention for agitation in people with dementia in care homes: a single-blind, cluster-randomised controlled trial. The Lancet. Psychiatry. 2019;6(4):293–304.30872010
39 Appelhof B, Bakker C, de Vugt ME, . Effects of a Multidisciplinary Intervention on the Presence of Neuropsychiatric Symptoms and Psychotropic Drug Use in Nursing Home Residents WithYoung-Onset Dementia: Behavior and Evolution of Young-Onset Dementia Part 2 (BEYOND-II) Study. Am J Geriatr Psychiatry. 2019;27(6):581–589.30799167
40 Ballard C, Corbett A, Orrell M, . Impact of person-centred care training and person-centred activities on quality of life, agitation, and antipsychotic use in people with dementia living in nursing homes: A cluster-randomised controlled trial. PLoS Medicine / Public Library of Science. 2018;15(2):e1002500.
41 Fukuda K, Terada S, Hashimoto M, . Effectiveness of educational program using printed educational material on care burden distress among staff of residential aged care facilities without medical specialists and/or registered nurses: Cluster quasi-randomization study. Geriatrics & gerontology international. 2018;18(3):487–494.29143427
42 Lichtwarck B, Selbaek G, Kirkevold O, . Targeted Interdisciplinary Model for Evaluation and Treatment of Neuropsychiatric Symptoms: A Cluster Randomized Controlled Trial. Am J Geriatr Psychiatry. 2018;26(1):25–38.28669575
43 Testad I, Mekki TE, Forland O, . Modeling and evaluating evidence-based continuing education program in nursing home dementia care (MEDCED)--training of care home staff to reduce use of restraint in care home residents with dementia. A cluster randomized controlled trial. International Journal of Geriatric Psychiatry. 2016;31(1):24–32.25845462
44 Galik E, Resnick B, Lerner N, . Function Focused Care for Assisted Living Residents With Dementia. Gerontologist. 2015;55 Suppl 1:S13–26.26055774
45 Zwijsen SA, Smalbrugge M, Eefsting JA, . Coming to grips with challenging behavior: a cluster randomized controlled trial on the effects of a multidisciplinary care program for challenging behavior in dementia. J Am Med Dir Assoc. 2014;15(7):531.e1–531.e10.
46 Chenoweth L, Forbes I, Fleming R, . PerCEN: a cluster randomized controlled trial of person-centered residential care and environment for people with dementia. International Psychogeriatrics. 2014;26(7):1147–60.24666667
47 Karlin BE, Visnic S, McGee JS, . Results from the multisite implementation of STAR-VA: a multicomponent psychosocial intervention for managing challenging dementia-related behaviors of veterans. Psychological Services. 2014;11(2):200–8.23937081
48 van de Ven G, Draskovic I, Adang EM, . Effects of dementia-care mapping on residents and staff of care homes: a pragmatic cluster-randomised controlled trial. PLoS ONE [Electronic Resource]. 2013;8(7):e67325.23844003
49 Rapp MA, Mell T, Majic T, . Agitation in nursing home residents with dementia (VIDEANT trial): effects of a cluster-randomized, controlled, guideline implementation trial. J Am Med Dir Assoc. 2013;14(9):690–5.23827658
50 Cohen-Mansfield J, Thein K, Marx MS, . Efficacy of nonpharmacologic interventions for agitation in advanced dementia: a randomized, placebo-controlled trial. Journal of Clinical Psychiatry. 2012;73(9):1255–61.23059151
51 Deudon A, Maubourguet N, Gervais X, . Non-pharmacological management of behavioural symptoms in nursing homes. International Journal of Geriatric Psychiatry. 2009;24(12):1386–95.19370714
52 Chenoweth L, King MT, Jeon YH, . Caring for Aged Dementia Care Resident Study (CADRES) of person-centred care, dementia-care mapping, and usual care in dementia: a cluster-randomised trial. Lancet Neurology. 2009;8(4):317–25.19282246
53 Chapman DG, Toseland RW. Effectiveness of advanced illness care teams for nursing home residents with dementia. Social Work. 2007;52(4):321–9.18232242
54 Cohen-Mansfield J, Libin A, Marx MS. Nonpharmacological treatment of agitation: a controlled trial of systematic individualized intervention. Journals of Gerontology Series A-Biological Sciences & Medical Sciences. 2007;62(8):908–16.17702884
55 Fossey J, Ballard C, Juszczak E, . Effect of enhanced psychosocial care on antipsychotic use in nursing home residents with severe dementia: cluster randomised trial. BMJ. 2006;332(7544):756–61.16543297
56 Teri L, Huda P, Gibbons L, . STAR: a dementia-specific training program for staff in assisted living residences. Gerontologist. 2005;45(5):686–93.16199404
57 Ballard C, Orrell M, Zhong SY, . Impact of antipsychotic review and nonpharmacological interventionon antipsychotic use, neuropsychiatric symptoms, and mortality in people with dementia living in nursing homes: A factorial cluster-randomized controlled trial by the well-being and health for people with dementia (WHELD) program. American Journal of Psychiatry. 2016;173(3):252–262.26585409
58 Kovach CR, Logan BR, Noonan PE, . Effects of the serial trial intervention on discomfort and behavior of nursing home residents with dementia. American Journal of Alzheimer’s Disease and other Dementias. 2006;21(3):147–155.
59 Eritz H, Hadjistavropoulos T, Williams J, . A life history intervention for individuals with dementia: A randomised controlled trial examining nursing staff empathy, perceived patient personhood and aggressive behaviours. Ageing & Society. 2016;36(10):2061–2089.
60 Mork Rokstad AM, Rosvik J, Kirkevold O, . The effect of person-centred dementia care to prevent agitation and other neuropsychiatric symptoms and enhance quality of life in nursing home patients: A 10-month randomized controlled trial. Dement Geriatr Cogn Disord. 2013;36(5–6):340–353.24022375
61 Leone E, Deudon A, Robert P. Motivation, engagement and verbal/motor stimulation in severe dementia-The STIM-EHPAD study. Revue de Neuropsychologie, Neurosciences Cognitives et Cliniques. 2012;4(2):114–122.
62 Moniz-Cook E, Hart C, Woods B, . Challenge Demcare: management of challenging behaviour in dementia at home and in care homes - development, evaluation and implementation of an online individualised intervention for care homes; and a cohort study of specialist community mental health care for families. 2017.
63 Smeets CHW, Smalbrugge M, Koopmans R, . Can the PROPER intervention reduce psychotropic drug prescription in nursing home residents with dementia? Results of a cluster-randomized controlled trial. International Psychogeriatrics. 2021;33(6):577–586.32431251
64 Pieper MJ, Francke AL, van der Steen JT, . [Effects of a stepwise approach to behavioural problems in dementia: a cluster randomised controlled trial]. Nederlands Tijdschrift voor Geneeskunde. 2016;160:D409.27299496
65 McCabe MP, Bird M, Davison TE, . An RCT to evaluate the utility of a clinical protocol for staff in the management of behavioral and psychological symptoms of dementia in residential aged-care settings. Aging & Mental Health. 2015;19(9):799–807.25319535
66 Denormandie P, Dubost V, Marigot-Outtandy D, . [Comparative study of two on aged care-based occupational (professional) training in medical home for aged and dependent patients with neuropsychiatric behaviors]. Geriatrie Et Psychologie Neuropsychiatrie Du Vieillissement. 2014;12(2):163–79.24939404
67 Irvine B, Billow MB, Gates DM, . An internet training to reduce assaults in long-term care. Geriatric Nursing. 2012;33(1):28–40.22209192
68 Irvine AB, Billow MB, Gates DM, . Internet training to respond to aggressive resident behaviors. Gerontologist. 2012;52(1):13–23.22038338
69 Wingenfeld K, Seidl N, Ammann A. [Preventing disruptive behavior of nursing home residents]. Zeitschrift fur Gerontologie und Geriatrie. 2011;44(1):27–32.
70 Bakker TJ, Duivenvoorden HJ, van der Lee J, . Integrative psychotherapeutic nursing home program to reduce multiple psychiatric symptoms of cognitively impaired patients and caregiver burden: randomized controlled trial. Am J Geriatr Psychiatry. 2011;19(6):507–20.20808147
71 Testad I, Ballard C, Bronnick K, . The effect of staff training on agitation and use of restraint in nursing home residents with dementia: a single-blind, randomized controlled trial. Journal of Clinical Psychiatry. 2010;71(1):80–6.20129008
72 Davison TE, McCabe MP, Visser S, . Controlled trial of dementia training with a peer support group for aged care staff. International Journal of Geriatric Psychiatry. 2007;22(9):868–73.17191270
73 Testad I, Aasland AM, Aarsland D. The effect of staff training on the use of restraint in dementia: a single-blind randomised controlled trial. International Journal of Geriatric Psychiatry. 2005;20(6):587–90.15920716
74 Gates D, Fitzwater E, Succop P. Reducing assaults against nursing home caregivers. Nursing Research. 2005;54(2):119–27.15778653
75 Wilkes L, Fleming A, Wilkes BL, . Environmental approach to reducing agitation in older persons with dementia in a nursing home. Australasian Journal on Ageing. 2005;24(3):141–145.
76 Haddad KE, de Souto Barreto P, Gerard S, . Effect of Relocation on Neuropsychiatric Symptoms in Elderly Adults Living in Long-Term Care. J Am Geriatr Soc. 2018;66(11):2183–2187.30296336
77 Smith R, Mathews RM, Gresham M. Pre- and postoccupancy evaluation of new dementia care cottages. American Journal of Alzheimer’s Disease and other Dementias. 2010;25(3):265–275.
78 Bowers L, James K, Quirk A, . Reducing conflict and containment rates on acute psychiatric wards: The Safewards cluster randomised controlled trial. Int J Nurs Stud. 2015;52(9):1412–22.26166187
79 Fletcher J, Hamilton B, Kinner SA, . Safewards impact in inpatient mental health units in Victoria, Australia: Staff perspectives. Frontiers in Psychiatry. 2019;10(JULY).
80 Narevic E, Giles GM, Rajadhyax R, . The effects of enhanced program review and staff training on the management of aggression among clients in a long-term neurobehavioral rehabilitation program. Aging & Mental Health. 2011;15(1):103–12.20924812
81 Ballard C, Orrell M, YongZhong S, . Impact of Antipsychotic Review and Nonpharmacological Intervention on Antipsychotic Use, Neuropsychiatric Symptoms, and Mortality in People With Dementia Living in Nursing Homes: A Factorial Cluster-Randomized Controlled Trial by the Well-Being and Health for People With Dementia (WHELD) Program. American Journal of Psychiatry. 2016;173(3):252–62.26585409
82 Chenoweth L, Forbes I, Fleming R, . PerCEN: A cluster randomized controlled trial of person-centered residential care and environment for people with dementia. International Psychogeriatrics. 2014;26(7):1147–1160.24666667
83 Erratum: Effects of a Stepwise Multidisciplinary Intervention for Challenging Behavior in Advanced Dementia: A Cluster Randomized Controlled Trial (J Am Geriatr Soc, 64, 2016 (261-269), 10.1111/jgs.13868). J Am Geriatr Soc. 2016;64(6):1383.
84 Chenoweth L, King MT, Jeon Y-H, . Caring for Aged Dementia Care Resident Study (CADRES) of person-centred care, dementia-care mapping, and usual care in dementia: A cluster-randomised trial. Lancet Neurol. 2009;8(4):317–325.19282246
85 Jedele JM, Curyto K, Ludwin BM, . Addressing Behavioral Symptoms of Dementia Through STAR-VA Implementation: Do Outcomes Vary by Behavior Type? Am J Alzheimers Dis Other Demen. 2020;35:1533317520911577.32237994
86 Karel MJ, Teri L, McConnell E, . Effectiveness of Expanded Implementation of STAR-VA for Managing Dementia-Related Behaviors Among Veterans. Gerontologist. 2016;56(1):126–34.26185155
87 Mohr DC, Curyto K, Jedele JM, . Impact of STAR-VA on Staff Injury and Disruptive Behavior Reports in VA Nursing Homes. J Am Med Dir Assoc. 2022;23(7):1159–1165.e1.34473962
88 McConeghy KW, Curyto K, Jedele J, . Impact of an interdisciplinary intervention for distress behaviors in dementia on psychotropic drug use in Veterans Health Administration Community Living Centers: STAR-VA impact on psychotropic drug utilization. Geriatric Nursing. 2021;42(6):1533–1540.34739929
89 Karlin BE. Results from the multisite implementation of STAR-VA: a multicomponent psychosocial intervention for managing challenging dementia-related behaviors of veterans. Psychological services. 2014;11(2):200–208.23937081
90 Lawton MP. Residential environment and self-directedness among older people. American Psychologist. 1990;45(5):638–640.2350081
91 Bandura A. Social learning theory. Englewood Cliffs, NJ: Prentice-Hall. 1977.
92 Ekman P. An argument for basic emotions. Cognition & Emotion, 6(3–4), 169–200. 1992.
93 Carver CS, Scheier MF. Origins and functions of positive and negative affect: A control-process view. Psychol Rev. 1990;97(1):19–35.
94 Watson D, Tellegen A. Toward a consensual structure of mood. Psychol Bull. 1985;98(2):219–35.3901060
95 Livingston G, Kelly L, Lewis-Holmes E, . Non-pharmacological interventions for agitation in dementia: Systematic review of randomised controlled trials. The British Journal of Psychiatry. 2014;205(6):436–442.25452601
96 CMS. Guiding an Improved Dementia Experience (GUIDE) Model. Available at: https://www.cms.gov/priorities/innovation/innovation-models/guide. Accessed September 11, 2023.
97 ASPE. National Plan to Address Alzheimer’s Disease. Available at: https://aspe.hhs.gov/collaborations-committees-advisory-groups/napa/napa-documents/napa-national-plan#:~:text=National%20Plan%20establishes%20six%20ambitious,Treat%20AD%2FADRD%20by%202025. Accessed September 11, 2023.
98 Kuring JK, Mathias JL, Ward L. Risk of Dementia in persons who have previously experienced clinically-significant Depression, Anxiety, or PTSD: A Systematic Review and Meta-Analysis. J Affect Disord. 2020;274:247–261.32469813
99 van Duinen-van den IJCL, Appelhof B, Zwijsen SA, . Behavior and Evolution of Young ONset Dementia part 2 (BEYOND-II) study: an intervention study aimed at improvement in the management of neuropsychiatric symptoms in institutionalized people with young onset dementia. International Psychogeriatrics. 2018;30(3):437–446.28595662
100 van Duinen-van den Ijssel JCL, Bakker C, Smalbrugge M, . Effects on staff outcomes from an intervention for management of neuropsychiatric symptoms in residents of young-onset dementia care units: A cluster randomised controlled trial. Int J Nurs Stud. 2019;96:35–43.30979401
101 Romeo R, Zala D, Knapp M, . Improving the quality of life of care home residents with dementia: Cost-effectiveness of an optimized intervention for residents with clinically significant agitation in dementia. Alzheimer’s & Dementia. 2019;15(2):282–291.
102 Klapwijk MS, Caljouw MA, Pieper MJ, . Change in quality of life after a multidisciplinary intervention for people with dementia: A cluster randomized controlled trial. International Journal of Geriatric Psychiatry. 2018;33(9):1213–1219.
103 Rosvik J, Engedal K, Kirkevold O. Factors to make the VIPS practice model more effective in the treatment of neuropsychiatric symptoms in nursing home residents with dementia. Dement Geriatr Cogn Disord. 2013;37(5–6):335–346.
104 van de Ven G, Draskovic I, van Herpen E, . The economics of dementia-care mapping in nursing homes: a cluster-randomised controlled trial. PLoS ONE [Electronic Resource]. 2014;9(1):e86662.24489762
105 van de Ven G, Draskovic I, Adang EM, . Improving person-centred care in nursing homes through dementia-care mapping: design of a cluster-randomised controlled trial. BMC Geriatrics. 2012;12:1.22214264
106 Pieper MJ, Francke AL, van der Steen JT, . Effects of a Stepwise Multidisciplinary Intervention for Challenging Behavior in Advanced Dementia: A Cluster Randomized Controlled Trial. J Am Geriatr Soc. 2016;64(2):261–9.26804064