# ACKNOWLEDGMENTS

The authors are grateful to Liz Wing for editorial support and Jessica Fulton for reference screening efforts, external peer reviewers, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Michele Karel, PhD
  National Mental Health Director, Geriatric Mental Health
  Office of Mental Health & Suicide Prevention
  Department of Veterans Affairs

## Technical Expert Panel

To ensure robust, scientifically relevant work, the technical expert panel (TEP) guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members included:

- Maureen Haske-Palomino, DNP, MSN, GNP-BC
  Chief, Specialty and Inpatient Advanced Practice Providers
  ONS/Madison VAMC

- Scott Hutton, PhD, RN, MBA, FAAN
  Director of Operations
  Workplace Violence Prevention Program, OMHSP

- Steve Weintraub, MD, MS
  Chief of the Division of Hospital Medicine
  St. Louis VAMC

- Marianne Shaughnessy, PhD, AGPCNP-BC, GS-C, FAAN
  Director
  Geriatric Research, Education and Clinical Centers