# DISCUSSION

Across 43 studies evaluating the impact of health care team-focused interventions on the management of distress behaviors among older adults, the majority of the available literature focused on the evaluation of interventions in the long-term residential health care setting among patients with dementia. Most interventions were fairly complex with multiple active components. Activities were intended to address multiple HCW behaviors and relied on a high level of interaction between intervention activities. Interventions incorporating activities focused only on HCWs through education or skills development may have some short-term benefit on distress behaviors, but there is no evidence supporting longer-term reductions in distress behavior or benefit on patient quality of life. Interventions that included both HCW education and training, as well as structured patient care activities, were found to improve quality of life and reduce the odds of antipsychotic use; while results were inconclusive about reducing patient distress, these intervention effects were generally in the direction of being beneficial. The few studies that examined staff-level outcomes of long-term health care setting interventions did not observe beneficial effects. There were few studies that examined interventions involving transitions in locations of care or that evaluated multi-faceted interventions from inpatient mental health settings.

The certainty of evidence (COE) ranged from very low to high certainty (Table 8). Within the patient-only intervention category, only 1 study was eligible for GRADE given the few studies in this category and inconsistent effect estimate reporting. This study showed moderate COE of no effect of patient-only interventions on quality of life. Studies in the HCW-only intervention category were graded as low or very low COE due to risk of bias, inconsistency, and serious imprecision. Specifically, 3 studies showed low COE of no effect of HCW interventions on CMAI; 4 studies showed very low COE of no effect on NPI; and 2 studies showed low COE of no effect on quality-of-life outcomes. Eight studies in the HCW-/patient-focused intervention category were rated as high COE for the reduction in antipsychotic use. Eleven showed moderate COE that the health care teams and patient interventions reduced distress behaviors using the CMAI, and 9 showed moderate COE of a reduction using the NPI measure. We also found moderate COE of an increase in quality of life in 8 studies evaluating health care teams and patient interventions. One study in the health care teams and patient and environment intervention category showed moderate COE of no effect of the intervention on antipsychotic use. In the same category, 3 studies showed moderate COE of no effect of the interventions on CMAI outcomes.

Our findings build on those of prior reviews. In particular, a 2016 AHRQ review of nonpharmacologic interventions on agitation and aggression in patients with dementia evaluated a variety of interventions for community settings, nursing homes, or assisted living facilities.^25^ They grouped long-term setting care models based on underlying theory and approach, specifically dementia care mapping, person-centered care, emotion-oriented care, and interventions to reduce antipsychotics. They found low strength of evidence that the effects of the first 2 are no different from usual care and insufficient evidence to draw conclusions on the latter 2. We included 15 of the studies found in the AHRQ review but grouped studies differently for analysis to capture the multi-level nature of identified interventions and overlapping approaches.

Table 8 Certainty of Evidence

Outcome | Number of Studies | Findings | Certainty of Evidence (Rationale)
Patient Only
CMAI | 1 RCT; (73 patients) | Effect estimate NR | Not possible to assess
Quality of life | 1 RCT; (73 patients) | Effect estimate for the adjusted analysis NR | Moderate; (Downgraded for serious imprecision)
Health Care Worker Only
Antipsychotics | 1 RCT; (274 patients) | Effect estimate NR | Not possible to assess
CMAI | 3 RCTs; (898 patients) | Mean difference for 1 study was −0.4, p values ranged from 0.078 to 0.8226 in 2 studies, 1 study showed a decrease compared to control arm. | Low; (Downgraded for serious risk of bias and serious imprecision)
NPI | 4 RCTs; (980 patients) | One study reported mean difference of −0.84, 1 reported F statistic of 4.78, 1 reported a z score of −2.15, and 1 didn’t report an effect estimate. P values ranged from 0.726 to 0.029 across 4 studies. | Very low; (Downgraded for serious risk of bias, serious inconsistency, and serious imprecision)
Quality of life | 2 RCTs; (624 patients) | One study reported a mean difference of 0.09 and a p value of 0.9657. One study reported an increase at 8 weeks but not at 20 weeks. | Low; (Downgraded for serious inconsistency, and serious imprecision)
Health Care Worker and Patient
Antipsychotics | 8 RCT; (3,476 patients) | SMD = 0.43, 95% CI [0.22, 0.84] | High; (Not downgraded)
CMAI | 11 RCT; (4,940 patients) | SMD = −0.31, 95% CI [−0.78, 0.16] | Moderate; (Downgraded for serious ROB)
NPI | 9 RCTs; (3,772 patients) | SMD = −0.47, 95% CI [−1.18, 0.24] | Moderate; (Downgraded for serious ROB)
Quality of life | 8 RCTs; (4,036 patients) | SMD = 0.71, 95% CI [0.39, 1.04] | Moderate; (Downgraded for serious imprecision)
Health Care Worker, Patient, and Environment
Antipsychotics | 1 RCT; (336 patients) | Difference between groups at 4 months 0.69 (p value 0.584) and 0.44 (p value 0.273) at 12 months | Moderate; (Downgraded for serious imprecision)
CMAI | 3 RCTs; (982 patients) | Mean difference in 1 study was −0.12 at 4 months to −0.06 at 12 months. The other studies did not report effect estimates. P values ranged from 0.729 to 0.05. | Moderate; (Downgraded for serious imprecision)

Abbreviations. CMAI=Cohen-Mansfield Agitation Index; NPI=Neuropsychiatric Inventory.

Reducing agitation or neuropsychiatric symptoms was the stated primary objective of most included studies. However, somewhat surprising was the lack of clear impact on patient distress, specifically agitation as measured by the CMAI or multiple neuropsychiatric behaviors and symptoms as measured by the NPI. It is noteworthy that for both instruments, patient distress level was reported by the staff receiving the intervention and not the patients themselves. It is possible that there was an increase in recognition of agitation behaviors due to intervention training or priming effect that balanced out any positive impact by the intervention. Meta-analyses of these outcomes were not statistically significant, which may be driven by a number of factors including heterogeneity of included complex intervention designs, small sample sizes of some included studies, and variation in effects across studies. Because benefits were apparent in some studies, results of these syntheses do not conclusively rule out a beneficial effect of interventions with both patient and HCW activities on patient distress. Instead, findings suggest that there may be contextual and intervention design factors that differ across studies and may contribute to intervention effectiveness. Indeed, the substantial variability in interventions designed to impact the same outcome suggests that results of meta-analysis should be viewed as secondary to findings from the most rigorous individual studies.

Reassuringly, we found evidence of a meaningful improvement in quality of life with interventions acting at both the HCW and patient level, even without a clear pattern of impact on agitation. One explanation is that the impact of these interventions could be felt on overall patient affect rather than distress behaviors. Affect, behavior, and mood are interconnected but distinct concepts in psychology, each contributing to our understanding of emotional and psychological experiences,^92–94^ and the link may not be apparent or as strong as anticipated. Given that we found a meaningful improvement in quality of life with interventions acting at both the HCW and patient level, there may be a few mechanisms of action at play that relate to improvements in affect and thereby improve mood over time. One example is that establishing a consistent daily schedule and structured routine can help reduce confusion and anxiety. Another mechanism might relate to social engagement. Promoting social interactions and engagement with health care workers and/or caregivers can reduce feelings of isolation and may enhance opportunities for group activities and companionship. It does not necessarily fully alter agitation, but it may improve quality of life.^54,95^ One challenge with this body of literature is the wide array of outcomes and intervention activities, which makes it difficult to evaluate the mechanism of action and related effect. Greater specificity and clarification regarding the intended mechanism of action for each outcome would be beneficial for this field moving forward.

Of note, we found limited data describing the impact of interventions on clinical team members or the potential mechanism of effect on this key group. Available data came from 6 studies and measured a variety of disparate constructs (eg, burnout, self-efficacy in caring for patients with dementia, job satisfaction). Regardless of the intervention components (ie, staff, patient, environment), there was consistency in results, in that there was no effect of these interventions on staff-level outcomes. Understanding the impact on HCWs of interventions designed to improve the management of distress behaviors is critical given the shortage of HCWs in long-term care settings and high rates of burnout and turnover. Some HCW outcomes, such as burnout and job stress, may be hard to impact by the types and duration of interventions included in this review because the determinants of these constructs stem from ever-evolving, system-level challenges and complications that exceed challenging interactions with patients with distress behavior (eg, understaffing, inadequate wages, job culture). Outcomes that measure more proximal experiences and focus on the relationship between staff and the specific person or people with dementia may be more sensitive to intervention-related effects (eg, self-efficacy with managing distress behaviors).

## Clinical Implications

In the context of an aging population, health care systems and long-term care facilities manage increasingly complex patients, many of whom may exhibit behaviors reflecting distress due to unaddressed personal needs and behavioral manifestations of an underlying illness or disease regardless of distress. Such behaviors can be further exacerbated by triggers or a stressful environment. The goal is not necessarily to eradicate challenging behavior but to find optimal ways to curb these behaviors and help staff be more aware of how they can empower themselves and the patient in managing these symptoms. The true goal in dementia care, or any other illness that causes distress behaviors, should transcend the focus on reducing agitation or aggression, and instead should be to improve and address patient needs. However, distress behaviors can also cause distress for HCWs and overwhelm limited resources in long-term care settings, restricting the ability to identify appropriate safe care settings for older individuals and placing tremendous pressure on family members.

Health care systems seeking to better equip health care teams to provide optimal patient-centered management of distress behaviors will need to look beyond interventions that are directed solely at health care team members or that only address patient care management patterns. The findings from this review point to the importance of multi-level interventions with activities that target health care team members, patient evaluation and management, and, likely, environmental or policy structures. This is in keeping with recent trends in care for older adults with cognitive impairment that call to enhance the quality and efficiency of care, caregiver training, and interdisciplinary longitudinal care.^96,97^ The necessity for such complexity requires anticipation and attention to real world contextual factors that will require investment of time and resources to ensure successful, high-fidelity adoption especially across community-based long-term care facilities with widely varying resources and contexts. The VA has multiple resources as a national integrated health care system including long-term care as well as extensive implementation science expertise that could be leveraged for future multi-level interventions.

## Limitations

It is important to note limitations of both the identified literature and our approach to conducting this review. With respect to the identified literature, the majority of included studies focused on care for patients with dementia in long-term care settings. While this field is on the forefront of managing distress behaviors, there are likely strategies and interventions being used in other settings (eg, inpatient general medicine) that could be applied across patient populations that have not made it into the published peer reviewed literature. Moreover, the interventions were almost universally complex in nature, combining components directed at multiple behaviors and clinical practices. Therefore, it was not possible to group studies for analysis based on individual intervention components (eg, antipsychotic medication review or individualized care planning) to determine which were most effective. After much consideration, we grouped studies based on intervention components identified conceptually in alignment with clinical guidance used to care for this patient population in practice. This approach likely explains the important heterogeneity in effects found in our meta-analyses. Other approaches might have led to different results. In addition, we had sought to identify interventions focused on transitions between care settings (eg, inpatient to skilled nursing facilities) and found very little addressing this vulnerable time point. Many studies described interventions with insufficient detail for replication and appropriate fidelity monitoring. We note that staff turnover is often quite high in long-term care settings, and few included studies actually reported the rates of turnover. High turnover of staff could limit the impact of interventions dedicated to skills training and knowledge gain given the need to retrain new staff. Included studies were conducted across multiple countries, which could introduce local cultural differences and heterogeneity of regulations and clinical settings in a way that impacts how distress behaviors are managed.

There were multiple limitations with respect to the type and detail provided on outcomes reported. First, the specific definition of distress behaviors varied across studies. In addition, there were limited data on adverse events, and it was difficult to compare adverse events across studies because of differing definitions of, and time points for, measuring adverse events. For example, the definition of falls was either not explicit or varied across studies: an observed fall was an adverse event in 1 study, but other study teams did not specify whether the fall was defined as needing medical treatment or was self-reported). Similarly, there was relatively limited detail on clinical staff-level outcomes for these interventions, which is problematic because 1 of the desired outcomes of improved distress behavior management is reducing the stress and burden on staff caregivers. Further, there was no information on how these interventions impact health care utilization. We were frequently unable to pool all identified studies for a given outcome due to heterogeneity of timing of follow-up, approach to measurement, and lack of reporting of an ICC or verification that clustering was incorporated into the analytic model. This final issue is significant in this field of study as a cluster-randomized trial is the most appropriate study design to evaluate interventions delivered at the clinic or care team level, and meta-synthesis is only valid with incorporation of statistical methods to account for the effect of clustering.

In order to focus the scope of the review, we did not include search terms or eligibility criteria that would have allowed inclusion of workplace violence. Nor did we seek to include literature employing trauma-informed care, which could be informative. Literature in this area may offer translatable insights that could apply to our target population of interest. In addition, it is possible we missed studies that evaluated interventions that were not focused specifically on distress behavior management but which could have had a secondary impact. In particular, we excluded studies focused on managing delirium, as we considered the implicit short-term nature of this condition to be a distinct construct from persistent or recurrent distress behaviors with different underlying causes; however, it is possible that interventions designed to address delirium could provide relevant lessons. We purposefully did not limit the sample to studies focused on older adults with dementia in order to identify potentially effective interventions from other patient populations. However, all the studies for KQ1 focused primarily on patients with dementia. Finally, we limited our data abstraction and analysis to studies found to have low or moderate risk of bias, though studies having a higher risk of bias could provide ideas about intervention types to explore for future study.

## FUTURE RESEARCH

In Table 9, we make suggestions on how future studies can improve the current evidence base and move the field toward identifying more effective interventions to improve the care for older adults with distress behaviors. Expanding exploration of interventions in older adult populations without dementia will be critical. One specific population of relevance for the VA is aging Veterans with posttraumatic stress disorder (PTSD), a condition that can accelerate cognitive decline and may increase distress behaviors.^98^ Multi-level, theory-based interventions with clearly articulated mechanisms of action and alignment with intended effects measured at appropriate time points should be pursued and could provide key data needed to foster appropriate comparisons. When the goal is improving staff outcomes, higher system-level targets could be explored. After effective interventions are identified, it will be critical to develop robust, evidence-based appropriate approaches to the implementation of these complex interventions. To better understand the balance in cluster-randomized trials, greater description of site characteristics including staff turnover and leadership structure would be helpful.

Similarly, more information about who delivered the intervention and the nature of their qualifications would support replication. After effectiveness is established, it will be important to explore how patients with different types of distress behaviors and health histories (eg, PTSD) might respond differently to such interventions. Further, implementation-based research and pragmatic trial designs may be useful methodologic approaches to advance this field.

Table 9 Evidence Gaps

PICOTS Domain | Areas for Future Exploration
Population | Older adults with complex behaviors at increased risk of distress behaviors who do not have dementia; Adults with varying stages of illness and comorbidity to explore heterogeneity of treatment effects
Intervention | Multi-level, theory-based interventions with clearly articulated mechanisms of action and alignment with intended effect; Consideration of higher-level components (eg, health care system culture or administration) for interventions intended to impact staff outcomes; Interventions that incorporate environmental changes; Interventions that incorporate trauma-informed care principles
Comparator | Clearly defined usual care (eg, staffing levels, organization factors); Health care staff education only
Outcomes | Harms (eg, self-injury, HCW injury); Health care utilization (eg, hospital readmission, ER visits); Proximal HCW outcomes (eg, self-efficacy for managing distress behaviors); Healthcare worker demonstrated competency in patient-centered approaches to distress behavior management; Healthcare worker turn-over; Studies using cluster-randomized trial designs should report the intraclass correlation coefficient (ICC) or models that account for the effect of clusters
Timing | Medium (3-6 months) and long-term outcomes (>6 months); If transitions of care, short-term after transition
Setting | Health care settings other than nursing homes and long-term care facilities (eg, inpatient medical/surgical units, ICUs, psychiatric inpatient settings); Transitions of care between health care settings or health care settings and home

## CONCLUSIONS

Novel interventions to reduce distress behaviors among older adults that feature both HCW education and training along with patient management intervention activities appear to have some beneficial impact on patient quality of life, reduction in antipsychotic use, and possibly distress behaviors. Less complex interventions, for example those focusing solely on HCW-only training, appear less likely to lead to desired effects. While more effective, complex interventions raise important questions about the challenges of high-fidelity implementation across varied long-term care settings for older adults with distress behaviors. Work remains to be done to determine the impact of these interventions on important health care staff outcomes such as burnout and systems-level outcomes such as utilization.