# RESULTS

## LITERATURE FLOW DIAGRAM

The literature flow diagram summarizes the results of the study selection process. A full list of excluded studies is provided in the Appendix.

Notes. ^a^ 56 records including 48 unique studies.

## OVERVIEW OF INCLUDED STUDIES

We identified 9,907 publications through database searching and an additional 34 articles through hand-searching citations of earlier systematic reviews. After deduplication and title and abstract screening, 212 articles remained for full-text review. 56 publications met eligibility criteria. Among these, there were 43 unique studies included for KQ1,^33–75^ 2 studies for KQ2,^76,77^ and 3 studies for KQ3.^78–80^ Studies were conducted in the US, Canada, Austria, Finland, France, Germany, Netherlands, Norway, Japan, Australia, and the United Kingdom. Table 1 provides an overview of included studies; additional study and intervention characteristics can be found in the Appendices).

Of the 43 unique studies in KQ1, 42 used more rigorous designs, and 1 program with 4 publications was implemented in the VA. These studies consisted of 1 interrupted time series study, 1 cluster nonrandomized controlled trial, 1 nonrandomized controlled before-after study, and 39 randomized controlled trials. The 39 randomized trials were assessed for risk of bias. The 29 studies determined to have low-to-moderate risk of bias were retained for data abstraction. Among these were 26 cluster-randomized trials, 1 factorial cluster-randomized trial, and 2 stepped-wedge randomized trials.

The 2 studies relevant to KQ2 consisted of 1 interrupted time series study and 1 other study. The 3 studies in KQ3 consisted of 1 cluster-randomized trial, 1 cross-sectional program evaluation, and 1 other. All 5 were retained for data abstraction.

Table 1 Evidence Profile

Number of Studies | 48 unique studies (56 articles)
Key Question | KQ1 (N = 43); KQ2 (N = 2); KQ3 (N = 3)
Study Designs | Cluster randomized controlled trial (N = 37); randomized controlled trial (N = 3); cluster nonrandomized trial (N = 1); controlled before-after (N = 1); interrupted time series (N = 1); non-EPOC interrupted time series (N = 2); program evaluation (N = 3)
ROBINS I Risk of Bias | Low (N = 0); moderate (N = 1); serious (N = 3); critical (N = 0)
ROB 2 Risk of Bias | Low (N = 2); Some concerns (N = 27); high (N = 10)
Prioritized for Analysis | KQ1 low/moderate risk of bias randomized studies (N = 29); KQ1 non-EPOC VA studies (N = 1); KQ2 (N=2); KQ3 (N = 3)
Study Year Range | 2005 to 2022
Number of Participants | 13,784 (N prioritized for analysis = 9,668)
Mean Age Range | 63.86 to 89.8 (NR = 4)
Countries | USA (N = 10); Europe (N = 18); Australia and New Zealand (N = 4); Japan (N = 1); Canada (N = 2)
Intervention Categories (KQ1) | Health care worker (HCW) only (N = 6); patient only (N = 3); patient and HCW (N = 17); patient and HCW and environment (N = 3)
Outcome Levels^a^ | Patient outcomes (N = 32); staff outcomes (N = 8); utilization outcomes (N = 0)

Notes.

a Eight studies reported more than 1 outcome type.

Abbreviations. EPOC=Effective Practice and Organisation of Care.

## KEY QUESTION 1 LONG-TERM RESIDENTIAL OR INPATIENT HEALTH CARE SETTINGS

### Key Points

- Many interventions included more than 1 active component and most often were directed at changing more than 1 HCW behavior; many interventions included a high level of interaction between intervention activities.
- The 3 interventions focusing on patient-facing aspects of the HCW role had mixed results on agitation. Only 1 study measured the impact on quality of life and found no significant effect.
- The 6 studies including HCW-focused intervention activities only suggest distress behaviors may be reduced when measured by the Neuropsychiatric Inventory (NPI) in the short term (ie, 30 days, > 8 weeks), but there is no evidence of an effect in the longer term (ie, 7 months, 8 months) or when measured by the Cohen-Mansfield Agitation Inventory (CMAI). There is no evidence of improvement in quality of life or reduction in antipsychotic use in the few studies reporting these outcomes.
- Seventeen interventions included both HCW-/patient-focused activities. A summary effect estimate from meta-analysis of 7 studies (9 interventions) did not show a significant reduction in agitation as measured by CMAI (SMD = −0.31, 95% CI [−0.78, 0.16]) or NPI (SMD = −0.47, 95% CI [−1.18, 0.24]) Effects varied substantially across studies. However, interventions were associated with a significant reduction in odds of antipsychotic use (OR = 0.79, 95% CI [0.69, 0.91]), and a medium to large improvement in quality of life as measured by DEMQOL-Proxy, EQ-5D index, or the QUALID (SMD = 0.71, 95% CI [0.39, 1.04]).
- Of the 3 interventions addressing health care teams, patients, and environment activities, only 1 showed an improvement in agitation, though only with short-term (ie, 4 months) but not longer-term follow-up (ie, 12 months). Antipsychotic use was not reduced.
- Six studies across multiple intervention types examined staff-level outcomes and none demonstrated a beneficial effect.
- Harms were measured using differing definitions at various time points across studies, making it difficult to draw conclusions.
- There were no health care utilization outcomes reported by the abstracted studies.

### Patient-Focused Intervention Activities Only

#### Intervention Characteristics

Three studies tested interventions that focused only on structured patient care activities delivered by HCWs, including a mechanism to detect or diagnose distress behaviors, assessment and care planning, ongoing support for distress behaviors, and/or medical management (Table 2).^50,54,59^ All studies took place in residential facilities and focused on care for patients with dementia. Two studies took place in the United States and described results from the Treatment Routes for Exploring Agitation (TREA) intervention,^50,54^ and 1 study took place in Canada.^59^ The TREA intervention applied a decision tree protocol to detect and diagnose distress behaviors and create tailored care plans for patients.^50,54^ The third study used a patient-centered care theoretical approach to create patient life histories for staff to review and use to inform care and their connections with the residents.^59^ Training for both interventions was delivered by members of the research team to nursing home staff.^50,59^ Staff training content, strategies, and dose were not clearly described.

#### Patient-Level Outcomes

##### Distress behaviors

[underlined: Agitation (CMAI).] The trial that randomized patients to patient life histories versus a medical history control arm^59^ included 73 patients and reported patient agitation using the CMAI. Results were reported at 2 time points that were from baseline to post intervention (which occurred at 20 days), and then follow-up at 46 days. No significant intervention effects were found as measured by CMAI. With the inclusion of cognitive impairment as a covariate in the model to assess differences between groups over time, the 2 groups did not have statistically different changes.

[underlined: Other measures of agitation]. The same life history study also measured agitation using the aggression behavior scale (ABS),^59^ while the other 2 studies examining the TREA intervention measured agitation using the agitation behavior mapping instrument (ABMI).^50,54^ For the life history study,^59^ analysis of ABS change scores from post intervention to follow-up was nonsignificant. Over the 10-day intervention of TREA^54^ during a 4-hour period of greatest agitation compared to the control group, there was a significant decrease in overall agitation from baseline (p = 0.002). In a second TREA study,^50^ overall, verbal, and nonaggressive physical agitation scores were significantly reduced compared with a control group during a 2-week observation period.

##### Quality of life

The life history study^59^ also examined changes in quality of life. Although unadjusted analyses found a significant difference favoring the intervention (p < 0.01), the finding was no longer significant after accounting for baseline characteristics including cognitive impairment.

Table 2 Summary of Evidence for Patient-Focused Intervention Activities

Number of Studies | 3 studies
ROB 2 Risk of Bias | Some concerns (N = 3)
Study Year Range | 2007 to 2016
Number of Participants | 365
Outcome Measured
CMAI | 1 intervention (1 inadequate data)
Quality of Life | 1 intervention (1 significant beneficial effect)

Abbreviations. CMAI=Cohen-Mansfield Agitation Index.

### Health Care Worker-Focused Intervention Activities Only

#### Intervention Characteristics

Six studies tested interventions activities focused solely on improving HCW skills and knowledge or altered HCW responsibilities or team roles (Table 3). These interventions primarily centered on 2 areas: (1) providing general education about dementia and/or (2) building staff skills to cope with distressed behaviors or implementing a tool, such as an assessment to identify the underlying causes of distress.^38,41,43,51,56,61^ These studies all took place in nursing homes or assisted living facilities and tested the interventions among individuals with dementia.

Five of the 6 studies included a general education activity that provided information to HCWs about dementia and the basic principles of distressed behavior.^38,41,51,56,61^ Five of 6 studies provided training in skills and intervention implementation. These studies tested skills-based interventions related to adopting methods of verbal and motor stimulation,^61^ directly addressing the distress behaviors,^51^ improving communication with residents,^38,56^ developing care plans,^38,56^ and using skills to reduce restraint and medication use.^43^

Reported training strategies included coaching,^51,61^ supervision,^38^ role play,^56^ case vignettes,^56^ and guidance groups to apply skills.^43^ All interventions were delivered in person. Interventions were generally delivered to all HCWs employed at the nursing home or assisted living facility.^38,41,43,51,56^ Intervention dose ranged from a single 2-hour session^41^ to a 2-day seminar followed by 6 monthly group meetings.^43^ The majority of studies delivered the intervention through multiple sessions,^38,43,51,56,61^ and 4 included supervision or coaching after the education intervention.^38,43,51,56^ While most studies did not report the training and credentials of the interventionist, 1 study did report that the training was provided by a clinical psychologist with geriatric mental health experience.^56^ The studies in this section did not refer to a theoretical model used to guide the intervention.

All but 1 study were found to have some concerns for risk of bias (ROB) with 1 low ROB. Common sources of concern for ROB for these studies include issues with randomization, missing patient data, deviations from the intended intervention, and outcome measurement.

#### Patient-Level Outcomes

##### Distress behaviors

[underlined: Agitation (CMAI).] Three studies reported patient agitation using the CMAI and none found a significant improvement. One French study of 16 nursing homes provided education on dementia and distress behaviors, as well as pocket training cards offering practical advice on how to handle such behaviors followed by ongoing feedback sessions over 2 months. The study found no significant difference in total CMAI score at 8 or 20 weeks compared to baseline (Appendix). A second study of 24 Norwegian care homes delivered an education program (MEDCED)^43^ intended to identify alternative interventions to restraints to manage distress behavior followed by guidance groups over 5 months also did not find a significant different in CMAI between groups at 7 months. Of note, this study reported a statistically significant reduction in restraint use across both intervention and control groups. The third study evaluated a 6-session manual-based intervention (MARQUE) followed by monthly supervision meetings and did not find a significant reduction in agitation at 8 months (adjusted mean difference [MD] = −0.40, 95% CI [−3.89, 3.09]). A fourth study evaluated a 2-day workshop of a dementia-specific training program (STAR)^56^ followed by 4 individual follow-up sessions over 2 months in 15 assisted living residences. This study reported a significant reduction in distress behaviors at 8 weeks using the agitated behavior in dementia scale (MD = −3.8 vs −0.5; p < 0.001).

[underlined: Neuropsychiatric Inventory (NPI).] Four studies assessed intervention effect on patient distress behaviors using the NPI total score. Two studies with longer-term outcomes found no intervention effect, while 2 with shorter-term outcomes found that the intervention reduced patient distress behaviors in the short run. An evaluation of a 120-minute staff training on behavioral and psychological symptoms of dementia at 17 residential care facilities in Japan significantly reduced total NPI score at 30 days compared to standard care (p = 0.029), though the method used for calculating the total NPI score appears atypical. The STAR study found a significant reduction in total NPI at 8 weeks (p = 0.031). The longer-term MEDCED study found a nonsignificant difference from baseline to 7 months between arms (5.7 vs 1.8; p = 0.207). Similarly, the MARQUE study^38^ reported a nonsignificant adjusted mean difference of −0.84 (95% CI [−5.51, 3.84]) at 8 months. Finally, 2 studies reported NPI subscales other than agitation without a total score.

##### Quality of life

Two studies reported patient quality of life and neither found an intervention effect. The 2-month French study provided dementia education, pocket training cards, and ongoing feedback sessions and found no difference at 20 weeks. The MARQUE intervention found no improvement in quality of life at 8 months either as rated by staff (MD = 0.09, 95% CI [−3.87, 4.05]) or by a family carer (MD = −0.03; 95% CI [−2.87, 2.82]).

##### Antipsychotic use

Two studies reported changes in medication use and neither found an intervention effect. The 2-month French study reported no change in mean number of psychotropic drugs (which included anticholinergics, memantine, antipsychotics, anxiolytics, and antidepressants) at baseline and at 20 weeks for intervention and control groups. The MEDCED intervention designed to reduce restraint use led to a small, nonsignificant increase in use of antipsychotics from 14.1% to 17.1% in both groups at 7 months.

Table 3 Summary of Evidence for Health Care Worker-Focused Intervention Activities

Number of Studies | 6 studies
ROB 2 Risk of Bias | Low (N = 1); some concerns (N = 5)
Study Year Range | 2005 to 2019
Number of Participants | 1,689
Outcome Measured
CMAI | 3 interventions (1 inadequate data; 2 no significant effect)
NPI | 4 interventions (1 inadequate data; 2 no significant effect; 1 significant benefit)
Antipsychotic Use | 3 interventions (2 inadequate data; 1 no significant effect)
Quality of Life | 2 intervention (2 no significant effect)

Abbreviations. CMAI=Cohen-Mansfield Agitation Index; NPI=Neuropsychiatric Inventory; ROB=risk of bias.

#### Staff Outcomes

Two of the 3 studies that assessed HCW-focused-only interventions used subscales of the caregiver burnout instrument (Maslach Burnout Inventory, MBI).^38,41^ The MBI has 3 subscales (emotional exhaustion, personal accomplishment, depersonalization). The 2 studies measured differences in scores at 30 days and 8 months, respectively, but neither found a difference between the intervention and control groups. The third study^56^ evaluated the STAR intervention (eg, workshops and follow-up sessions on activators and consequences of behavioral distress) in assisted living facilities and measured “sense of competence and satisfaction with patient care” and supervision and coworker relations over an 8 week follow-up period, but also did not find a difference in mean scores.

#### Utilization Outcomes

No included studies examined utilization outcomes.

### Health Care Worker and Patient-Focused Intervention Activities

#### Intervention Characteristics

Seventeen studies examined interventions directed at both direct patient care activities delivered by HCWs and HCW-focused trainings and role changes (Table 4).^34,37,39,40,42,45,48,49,53,55,58,62,81–83^ Two of the 17 examined this combination of strategies across multiple study arms.^49,60,84^ Studies were conducted in the Netherlands,^39,45,48,83^ UK^40,55,62,81^ USA,^53,58^ Australia,^82,84^ Canada,^37^ Germany,^49^ and Norway.^34,42,60^

Five studies examined different outcomes among different patient populations using similar principles inspired by WHELD,^40,81^ and dementia care mapping.^84^ All interventions took place in nursing home settings and, with the exception of 1 study,^34^ all examined outcomes exclusively in patients with dementia.

All studies implemented at least 2 distinct intervention activities, and 2 studies implemented 5 activities.^39,42^ The most common intervention activity across studies was assessing resident dementia and behaviors to inform individualized care plans.^34,37,39,40,42,45,48,49,53,58,62,81–83^ Other intervention activities that targeted patients included detection of distressed behaviors,^34,39,42,45,84^ medical management,^37,39,40,42,48,53,55,58,81,83^ and ongoing care for distressed behaviors through symptom monitoring, and, in some cases, monitoring how well the care plan was working.^39,40,42,48,53,58,83^ Most medical management activities focused on a review of resident medications, primarily antipsychotics.

The most common intervention activity focused directly on HCWs was education about a specific intervention or approach to reduce distressed behaviors.^34,37,40,42,45,48,49,51,55,58,60,62,81,82,84^ Topics ranged from how to implement a specific care program (eg, Coming to Grips with Challenging Behavior Care Program,^45^ dementia care mapping,^48,60,84^ and patient-centered care^40,55^) to how to perform case conferences,^34^ how to develop an individualized care plan,^62^ how to assess distressed behaviors using a specific tool,^37,49^ and how to improve communication skills with residents (social interaction arm).^81^ Several studies also tested the effect of general education for staff focused on dementia and distressed behaviors.^34,37,39,45,49,51,84^ Six studies also incorporated changes to how staff functioned as a team. For example, several studies implemented multidisciplinary case conferences or care meetings.^34,42,45,60^ Another study developed a process to create care plans that included input from nurse’s aides and other staff.^53^ Two studies trained staff to take on new roles.^34,60^

Among studies that reported intervention delivery mode, all but 1 had an in-person component,^34,37,39,42,45,49,53,55,58,60,81–84^ several had a telephone or teleconference component,^37,82,84^ and 1 was internet based.^62^ In 1 study, trainings were delivered by a multidisciplinary team comprised of nurses, physicians, and psychologists^39,49^; other interventions were delivered by trained (though credentials were unspecified) “therapists,”^40,62,81^ clinical social workers,^53^ patient-centered care experts,^82^ trained members of the research team,^34,37,55,60,84^ nurses,^34,58^ and dementia care mapping experts.^48,60^ Generally a multidisciplinary team of nursing home staff were trained in each study, including physicians,^37,39,42,45,53,81,83^ psychologists,^39,45,53^ social workers,^53^ nurses,^34,37,39,42,45,53,58,60,82–84^ care managers,^40,82,84^ nursing home staff,^40,45,48,49,55,60,81–84^ residents,^40^ and other staff (eg, physical therapists, occupational therapists, nutritionists, pharmacists^37,53,82^). Targeted professionals were most frequently nurses, nursing home staff, and physicians.

Training approaches and duration differed between studies. The most intensive training lasted 2 days a week for 10 months,^55^ and the study that offered the least amount of training provided a 3-hour lecture.^60^ Many studies used a combination of an initial training activity and follow-up supervision, coaching, or case conferences conducted in-person or via telephone.^34,37,40,42,55,58,82,84^ Some studies also offered different tiers of training to staff. For example, several studies provided a baseline training for multiple staff and additional training in the intervention methodology to onsite champions or intervention teams.^40,42,49,60^ In a few studies, only champions or site implementers received any training.^34,48,53,81,84^ Several studies mentioned theoretical underpinnings for the intervention, including person-centered care,^40,42,48,81^ normalization process theory,^62^ DICE models,^37^ cognitive behavioral theory,^42^ and the VIPs framework.^60^

#### Patient-Level Outcomes

##### Distress behaviors

[underlined: Agitation (CMAI).] Eleven studies (Table 4 and Appendix) assessed reductions in agitation using the CMAI.^40,42,45,48,49,55,62,81–84^ Of these, 5 reported reductions in agitation.^40,42,45,49,84^ Specifically, the WHELD intervention,^40^ which combined staff training, social interaction, and guidance on the use of antipsychotic medications in 69 UK care homes across a 9-month period, found significant reduction in agitation compared to treatment as usual (MD = −4.27, 95% CI [−7.39, −1.15]). In the CADRES study,^84^ which compared dementia care mapping and a person-centered care intervention to usual care, CMAI scores were lower in both intervention conditions over an 8-month period (dementia care: MD = 10.9, 95% CI [0.7 to 21.1]; person-centered care: MD = 13.6, 95% CI [3.3, 23.9]). Across a 10-month period, patients with dementia enrolled in the VIDEANT intervention^49^ (consisting of staff training, support, and activity therapy) exhibited significantly less agitation (aMD = 6.24, 95% CI [2.03, 14.14]) than patients in a usual care group. For dementia residents in the Grip on Challenging Behavior care program,^45^ their CMAI change scores were significantly improved compared to the pre-intervention control period (stepped-wedge design) between successive assessments (−2.5 points, 95% CI [−4.3, −0.6]). However, no significant effects were found for the control-to-intervention group compared with those who remained in the control group (0.0 points, 95% CI [−2.3, 2.4]). Last, in a stepwise multicomponent intervention (STA OP!) delivered to nursing home patients with advanced dementia, an overall reduction in agitation was observed compared to usual care from baseline to 6 months (MD = −4.07; 95% CI [−7.9, −0.24]). Finally, the Targeted Interdisciplinary Model for Evaluation and Treatment of Neuropsychiatric Symptoms (TIME) study reported significantly reduced agitation at 8 weeks (SMD = 0.23, p = 0.026) and 12 weeks (SMD = 0.29, p = 0.006) compared with usual care.^42^

Interventions in the remaining 6 studies did not significantly reduce agitation^48,55,62,81–83^ and 2 showed a nonsignificant reduction in agitation.^81,82^

In a meta-analysis of 7 studies (including 9 intervention conditions), health care worker- and patient-focused interventions did not lead to a significant reduction in patient agitation (SMD = −0.31, 95% CI [−0.78, 0.16]). This result may be attributable to substantial variation in effects across studies (95% PI [−1.38, 0.76]), including across studies of the same specific intervention (Figure 1).

Figure 1 Agitation (CMAI) Results

Four studies assessed reductions in agitation using CMAI subscales.^39,53,60,62^ The subscales examined included aggressive,^39,53^ agitation,^60^ physical,^53,62^ and verbal^39,53,62^ domains. Only 1 study of the 4 indicated significant reductions in physically nonaggressive behaviors. Specifically, this study^53^ examined the effectiveness of an advanced illness care team (AICTs) intervention for nursing home residents living with advanced dementia. The AICTs intervention focused on medical, meaningful activities, psychological, and behavioral domains. Compared to usual care, nursing home residents experienced a significant decrease in physically nonaggressive behaviors across an 8-week period (p < .05).

[underlined: Neuropsychiatric symptoms (NPI).] Nine studies examined intervention effects in reducing overall neuropsychiatric behaviors and symptoms using the NPI total scores.^34,42,45,48,60,62,81,83,84^ Three studies^60,81,83^ found significant intervention effects. An evaluation of the impact of antipsychotic review, social interaction, and exercise interventions on neuropsychiatric symptoms at 9-month follow-up indicated significant symptom improvement favoring antipsychotic review (MD = 7.37, 95% CI [1.53, 13.22]) and a social interaction intervention (SMD = 5.45, 95% CI [0.12, 10.77]).^81^ The STA OP! study^83^ also reported an improvement from baseline to 6 months (adjusted MD = −3.57 (95% CI [−6.30, −0.84]). The effects of a person-centered dementia intervention and the VIPS practice model (VPM) compared to education of the nursing home staff about dementia only were significant at 10 months (SMD = −2.7, 95% CI [−4.6, −0.7], SMD = −2.4, 95% CI [−4.1, −0.6], respectively).^60^ In addition, 1 evaluation of a dementia care mapping intervention found that NPI scores decreased in the usual care arm but not in the intervention arm (p = 0.022).

Of the other 5 intervention arms from 4 studies, 1 found a non-significant reduction in NPI score with delivery of an interdisciplinary model (TIME; SMD = −0.25, p = 0.053). Three found no intervention effects.^34,45,62^ The fifth study did not report a direct statistical comparison, but mean scores over follow-up showed a clinically significant reduction in NPI in the patient-centered care arm but not in the dementia-care mapping arm. For 3 of these, the NPI was the primary outcome for the study.^34,42,62^ Overall, the time period of these interventions ranged between 4 and 20 months.

Eight interventions from 5 studies were included in a meta-analysis that indicated a moderate, though nonsignificant, reduction in neuropsychiatric behaviors (SMD = −0.47, 95% CI [−1.18, 0.24]) at 6-11 months following HCW and patient-focused interventions. The prediction interval for this estimate was −2.40 to 1.46 (Figure 2), suggesting notable heterogeneity across studies.

Figure 2 Neuropsychiatric Symptoms (NPI) Results

A total of 6 studies examined reduction in neuropsychiatric symptoms using NPI subscales.^34,39,42,48,58,62^ The subscales covered affective,^34^ agitation,^34,39,48^ agitation/aggression,^39,42^ apathy,^34^ distress, frequency, and incidence,^62^ psychosis,^34^ and severity^62^ domains. Only 2 studies^34,42^ reduced agitation/aggression and apathy, respectively. In 1 Norwegian study of 33 nursing homes from 20 municipalities,^42^ the TIME intervention was implemented to target moderate-to-severe agitation compared to a control group. A significant between-group difference was evidenced in reducing agitation/aggression at 8 weeks (SMD = 0.32, p = 0.03) and at 12 weeks (SMD = 0.47, p = 0.002). In a secondary Norwegian study,^34^ the implementation of a modified comprehensive geriatric assessment alongside regular case conferencing reduced apathy symptoms among nursing home residents at 3 months (SMD = −0.5, 95% CI [−0.9, −0.05]).

The 4 studies that found no or nearly zero intervention effects (compared to usual care, control, or a brief education arm) on reducing NPI agitation subscale scores included a multidisciplinary intervention focused on education and management of neuropsychiatric symptoms,^39^ dementia care mapping,^48^ e-learning,^62^ and modified comprehensive geriatric assessment and case conferences.^34^

##### Other distress behaviors

Three studies reported other challenging behaviors^37,58,62^ and none found an intervention effect. The behaviors examined included aggression/wandering behavior as assessed by worsening behavioral symptoms using the Resident Assessment Instrument-Minimum Dataset v 2.0 (RAI-MDS),^37^ severity, frequency, and increase of resident behavior using the Challenging Behavior Scale (CBS),^62^ and the BEHAVE-Alzheimer’s Disease scale.^58^ An educational in-service intervention consisting of evidence-based tools to assess and monitor neuropsychiatric symptoms in dementia with monthly interprofessional team meetings found no effect at 12 months (OR = 0.96, 95% CI [0.8, 1.14]).^37^ An e-learning intervention found no effects to reduce the incidence of difficult, frequent, or behavioral symptoms in dementia from baseline to 4 and 7 months.^62^ The Serial Trial Intervention (STI) study^58^ focused on the assessment and management of people with late-stage dementia. Compared to control, no significant group differences were found in reducing wandering behaviors at 4 weeks (p = 0.50).

##### Quality of life

A total of 9 studies examined intervention effects to improve quality of life among patient- and health care worker-level interventions.^33,40,42,48,55,60,62,82,84^ Of these studies, 4 improved either overall quality of life using the DEMQOL-Proxy, EQ-5D index (self-report), the Quality of Life in Late-stage Dementia, the QUALID,^40,42,60^ or a facet of quality of life like restless tense behavior as assessed by the QUALIDEM observation tool.^33^ The WHELD (staff training and in person-centered care) intervention^40^ compared to treatment as usual found a significant mean difference in improving participant quality of life (MD = 2.54, 95% CI [0.81, 4.28]). The TIME intervention compared to a brief education intervention at 12 weeks (and not at 8 weeks) found a between-group difference in quality of life among those with late-stage dementia (SMD = 0.17, p = 0.044). Last, in a dementia care mapping (DCM) or a VIPS practice model (VPM) compared to control at 10 months, quality of life scores favored the DCM versus control arm (SMD = −3.0, 95% CI [−5.5, −0.6]). In the STA OP! intervention study^33^ compared to usual care, restless tense behavior symptoms (ie, facets of quality of life) improved at 3 months (95% CI [0.36, 1.54]). However, at 6 months the usual care group fared better in restless tense behavior symptoms (95% CI [−1.60, −0.36]).

Seven interventions from 5 studies were included in a meta-analysis measuring quality of life at 7 to 11 months after baseline and found a significant medium to large beneficial effect after HCW-/patient-focused interventions with an SMD of 0.71 (95% CI [0.39, 1.04]; Figure 3). Of note, the prediction interval for this effect estimate suggests marked heterogeneity of treatment effect, ranging from a small to large effect.

Figure 3 Quality of Life Results

##### Antipsychotic use

Eight studies assessed effects on antipsychotic medication use (Figure 4).^37,39,40,45,62,81,83,84^ Trials used a cluster-randomized design,^62,81,83^ stepped-wedge design,^37,39,45^ or RCT design.^40,84^ Four of the 8 studies reported changes in reducing antipsychotic medication use.^37,45,62,81^ Seven interventions from 6 studies were included in a meta-analysis and found a reduced odds of antipsychotic use at 6 to 12 months with HCW-/patient-focused interventions (OR = 0.79, 95% CI [0.69, 0.91]).

In a 9-month study^81^ that randomized patients to antipsychotic review, social interaction, or exercise alone or in combination, results suggest that antipsychotic review versus no antipsychotic review significantly reduced antipsychotic medication use (OR = 0.17, 95% CI [0.05, 0.59]). None of the other interventions (eg, social interaction vs no antipsychotic review; OR = 0.6, 95% CI [0.19, 1.91]) had a significant impact on medication use. The DEMCare e-learning intervention^62^ based on a functional analysis of dementia behaviors was compared to usual care, revealing a small nonsignificant reduction in medication use (chi square > 0.999) from baseline to 7-month follow-up. A multi-component intervention^37^ that included education in-service, monthly interprofessional team meetings, and evidence-based tools to address neuropsychiatric symptoms reported a reduction in odds of inappropriate antipsychotic prescribing from baseline to 12-month follow-up (OR = 0.73, 95% CI [0.58, 0.94]). In a 20-month study examining the Grip on Challenging Behavior care program,^45^ odds of antipsychotic prescribing were significantly lower compared with control (OR = 0.54, 95% CI [0.37, 0.80]). Similarly, in an enhanced psychosocial care intervention offering training and staff support in the care of patients with dementia,^55^ there was a significant 19.1% reduction in neuroleptic prescription use in the intervention group compared with control (95% CI [0.5%, 37.70%]). Finally, a trial of the VIDEANT intervention (consisting of staff training, support, and activity therapy) found that nursing home residents with dementia in the intervention group compared to controls received fewer neuroleptics (OR 0.79, [95% CI 0.64, 0.98]) within a 10-month period.^49^

Figure 4 Antipsychotic Use Results

##### Other medication use

In addition to the above, reductions in other medications such as anxiolytics, psychotropics, neuroleptics, and ChEI were examined in 4 studies.^39,45,49,55^ The BEYOND-II trial^39^ found no evidence of reduced use of anxiolytics (regression coefficient = −0.033, 95% CI [−0.095, 0.029]) nor any psychotropic medication (regression coefficient = −0.023, 95% CI [−0.09, 0.044]) from baseline to 6 months. Similarly, in an enhanced psychosocial care intervention offering training and health care teams support in the care of patients with dementia,^55^ reductions in psychotropics were nonsignificant with a weighted mean difference of −5.9 (95% CI [−27.2, 15.5]). No support for reduction in prescribed anxiolytics was found (ie, odds ratios were not significantly lower) after introducing the Grip on Challenging Behavior care program^45^ compared to control. Table 4 presents results for the HCW- and patient-focused interventions.

Table 4 Summary of Evidence for Health Care Worker and Patient-Focused Intervention Activities

Number of Studies | 17 studies
ROB 2 Risk of Bias | Low (N = 1); some concerns (N = 15), high (N = 1)
Study Year Range | 2006 to 2022
Number of Participants | 6,377
Outcome Measured
CMAI | 11 interventions (2 inadequate data; 5 no significant effect; 4 significant benefit)
NPI | 10 interventions (1 inadequate data; 4 no significant effect; 3 significant benefit; 2 significant detrimental effect)
Antipsychotic Use | 9 interventions (1 inadequate data; 6 no significant effect; 2 significant benefit)
Quality of Life | 9 interventions (7 no significant effect; 4 significant benefit)

Abbreviations. CMAI=Cohen-Mansfield Agitation Index; NPI=Neuropsychiatric Inventory; ROB=risk of bias.

#### Staff Outcomes

Two studies^48,62^ measured staff outcomes; there were no common measures (measures included quality of life as measured by the EQ-5D, attitudes toward people with dementia, and perceived self-efficacy in caring for people with dementia, MBI, stress symptomology, staff job satisfaction). Neither study demonstrated an improvement in staff outcomes at 4 to 8 months.

#### Utilization Outcomes

No included studies examined utilization outcomes.

### Health Care Worker, Patient, and Environment-Focused Intervention Activities

#### Intervention Characteristics

Three studies conducted in the United States tested similar interventions targeting patients, staff, and environment^35,36,44^ which were based on the social ecological model and social cognitive theory (Table 5). Intervention activities focused on HCWs included skills and implementation training that focused on providing proactive, function-focused care. All 3 interventions also targeted patient behaviors by training staff to develop tailored care plans for residents. One intervention also provided ongoing care to address resident distress by evaluating the effect of the care plan and instituted multidisciplinary team meetings.^36^ The interventions also included assessments of the physical settings and a review of residential care policies to inform modifications to the environment that would optimize function and physical activity for residents. All interventions were provided to staff in person by a trained nurse. Staff targeted by the training included nurses, social workers, and activity staff.^35,36,44^ One study also included families and residents in the training.^44^ Training was fairly intensive, ranging from 10 hours per week for 12^35^ or 6 months^44^ to 2 hours per month for 12 months.^36^

#### Patient-Level Outcomes

##### Distress behaviors

[underlined: Agitation (CMAI).] Three studies reported patient agitation using the CMAI; 2 of these studies did not find a significant improvement. One cluster-randomized trial consisted of 4 assisted living facilities, 96 patients, and 76 nursing staff delivering the Function Focused Care Intervention for the Cognitively Impaired (FFC-CI).^44^ The FFC-CI intervention is a 4-component intervention that teaches staff how to engage with patients with dementia in activities that improve function with the aim to reduce behavioral symptoms. Compared to a control group at 3 and at 6 months, no significant reductions in agitation were found as measured by CMAI (p = 0.18 and p = 0.49, respectively). A second study of 12 US-based nursing homes delivered a Function and Behavior Focused Care for the Cognitively Impaired (FBFC-CI) intervention compared to an educational control arm.^35^ The FBFC-CI is similar to the FFC-CI, with a joint focus on function and behavior care goals. There were no significant differences in agitation from baseline to 12 months, with a mean difference of −0.06 (95% CI [−2.41, 1.69]). The third study^36^ evaluated a 12-month, 4-component intervention facilitated by a research nurse who meets with a facility team champion and stakeholder for 2 hours per month, Function Focused Care for Assisted Living Using the Evidence Integration Triangle (FFC-AL-EIT), compared to an education-only arm. Between baseline and 4 months, there was a statistically, though likely not clinically, significant decrease in agitation in the FFC-AL-EIT group compared to the control (treatment group baseline of 14.79 decreased to 14.64 and the control group increased from 14.55 to 14.88, p = 0.045). At 12 months this difference was no longer significant (p = 0.17).

##### Antipsychotic use

One study that focused on the delivery of a FBFC-CI intervention compared to an educational control found no decrease in antipsychotic use at 12 months, mean difference −0.44 (95% CI [−2.27, .64)]).^35^

#### Staff Outcomes

The single study that examined an intervention with HCW, patient, and environment activities used staff-level outcomes related to self-efficacy and job satisfaction.^44^ There was no difference in scores at 3 or 6 months.

#### Utilization Outcomes

No included studies examined utilization outcomes.

Table 5 Summary of Evidence for Health Care Worker, Patient, and Environment-Focused Intervention Activities

Number of Studies | 3 studies
ROB 2 Risk of Bias | Some concerns (N = 3)
Study Year Range | 2015 to 2021
Number of Participants | 491
Outcome Measured
CMAI | 3 interventions (3 no significant effect)
Antipsychotic Use | 1 intervention (1 no significant effect)

Abbreviations. CMAI=Cohen-Mansfield Agitation Index; ROB=risk of bias.

### Harms (All Intervention Types)

Seven studies reported on patient harms in long-term residential or inpatient health care settings (Table 6).^37,52,55,57,62^ Studies included a range of adverse events, such as falls, hospitalizations, death, and composite endpoints of multiple incidents. Across studies, falls were the most commonly reported adverse event. In a randomized controlled trial of neuroleptic prescription reduction among British nursing home patients, there was no significant difference in the number of patients experiencing falls in the intervention group (91/175, 52%) versus the usual care group at 12 months (90/165, 54%), with a weighted mean difference of 2.6 (95% CI [18.7, 23.8]). A stepped-wedge trial to reduce inappropriate prescribing of antipsychotics in long-term care found no significant difference in the baseline (15.1; SD = 1.3) and 12-month (15.2; SD = 0.8) mean number of falls in the prior month (OR = 1.00, 95% CI [0.83, 1.21]). In an Australian pragmatic cluster-randomized trial of person-centered care, dementia care mapping, and usual care, the proportion of patients with falls decreased with dementia care mapping (change from baseline = −7%) but increased somewhat with person-centered care (change from baseline = 2%). At follow-up, 10% fewer falls were reported among patients receiving dementia care mapping compared with usual care (p = 0.02). Reported proportions were adjusted for clinical and demographic characteristics, but importantly, the baseline proportion of patients with falls was much lower in the usual care group than in the intervention groups. This may have attenuated the difference in fall rates between dementia care mapping and usual care groups.

Death was an adverse event or secondary outcome in 2 studies. The first was a cluster-randomized factorial controlled trial evaluating social interaction and/or a review of antipsychotic medication use that was conducted in people with dementia in 16 nursing homes across the United Kingdom and reported death as a secondary outcome. Patients who received the medication review had reduced mortality compared to those who did not receive a review, though this reduction was not statistically significant (OR = 0.67, 95% CI [0.39, 1.14]). An increase in social interaction was associated with significantly reduced mortality (OR = 0.26, 95% CI [0.13, 0.51]). A clustered, randomized implementation trial in 18 nursing homes in Berlin, Germany, implemented guidelines to reduce agitation and review medication use. During the study, 17 residents in the intervention group and 12 residents in the control group died (p = 0.57).

Hospitalization was also reported as an adverse event in the German study. 24 intervention group patients and 22 control group patients were hospitalized (p = 0.97). In a nonpharmacologic intervention in French nursing homes, a statistically significant difference in mean baseline hospitalizations was observed between the intervention (40, SD = 23) and control (49, SD = 37.1) groups (p < 0.05), but there was no significant difference noted at 8 or 20 weeks.

Finally, 2 studies used composite measures to assess adverse events. First, a cluster-randomized trial in the United Kingdom of a staff education and decision support system intervention in care homes used the composite outcome of serious adverse events (eg, death, life-threatening event, hospitalization, significant disability or incapacity, medically significant event, alleged or suspected abuse or neglect). Eighty participants in the e-learning intervention experienced a serious adverse event (80/420, 19%), compared to 55 out of 412 (13%) usual care patients. The authors did not perform a statistical analysis between the groups. Second, the Australian trial of person-centered care, dementia care mapping, and usual care also reported a composite endpoint of incidents, capturing falls, injuries, drug errors, and behavioral events. There was no statistically significant difference (p = 0.89) when comparing over time across the 3 arms: baseline (PCC 0.43%; DCM 0.40%; UC 0.25%), 4 months (PCC 0.53%; DCM 0.49%; UC 0.37%), and 8 months (PCC 0.44%; DCM 0.46%; UC 0.37%). The authors also separated the components of the composite endpoint to look at hospitalizations due to falls; however, they determined there were so few incidents that they did not report the number of incidents or complete statistical analysis.

Table 6 Results of Studies Reporting Harms

Study; N Clusters; N Patients; Primary Outcome | Outcome; Direction; Time Point | Results
Ballard, 2016^81^; 16 nursing homes; 277 patients randomized; Primary outcome: CMAI | Death; Lower = better; 9 months | Antipsychotic review vs no antipsychotic review OR = 0.67 (95% CI [0.39, 1.14]); p value: 0.15; Social interaction vs no social interaction OR = 0.26 (95% CI [0.13, 0.51]); p value: <0.001
Chenoweth, 2009^84^; 15 care sites; 289 patients randomized; Primary outcome: CMAI | Incidents (falls, injuries, drug errors, and behavioral events); Lower = better; 4 months; 8 months | Baseline; Person-centered care: 0.43%; Dementia care mapping: 0.40%; Usual care: 0.25%; 4 months; Person-centered care: 0.53%; Dementia care mapping: 0.49%; Usual care: 0.37%; 8 months; Person-centered care: 0.44%; Dementia care mapping: 0.46%; Usual care: 0.37%; Arm x time p value: 0.89
Chenoweth, 2009^84^; 15 care sites; 289 patients randomized; Primary outcome: CMAI | Falls; Lower = better; 4 months; 8 months | Baseline; Person-centered care: 0.32%; Dementia care mapping: 0.27%; Usual care 0.13%; 4 months; Person-centered care: 0.37%; Dementia care mapping: 0.24%; Usual care 0.27%; 8 months; Person-centered care: 0.34%; Dementia care mapping: 0.20%; Usual care: 0.30%; Mean difference between person-centered care and usual care: 0.15 (95% CI [0.02, 0.28]), p value: 0.03; Mean difference between dementia-care mapping and usual care: 0.24 (95% CI [0.08, 0.4]), p value: 0.02; 3 arms x time p value: 0.13
Fossey, 2006^55^; 12 nursing homes; 346 patients randomized; Primary outcome: neuroleptic use | Falls; Lower = better; 12 months | Training and staff support intervention: 19/175; Usual care: 90/165; Weighted mean difference between training and staff support and usual care: 2.6 (95% CI [−18.7, 23.8]), p value: 0.27
Kirkham, 2020^37^; 10 long-term care facilities; Primary outcome: antipsychotic use | Falls in the last 30 days; Lower = better; 12 months | OPAL intervention baseline mean: 15.1 (SD = 1.3); OPAL intervention at 12-month follow-up mean: 15.2 (SD = 0.8); OR = 1.00 (95% CI [0.83, 1.21]), p value: 0.98
Moniz-Cook, 2017^62^; 63 care homes; 832 patients randomized; Primary outcome: NPI | Serious adverse events (eg, death, life-threatening event, hospitalization, significant disability or incapacity, medically significant event, alleged or suspected abuse or neglect); Lower = better; 4 months; 7 months | e-learning intervention: 80/420; Usual care: 55/412

### Intervention Complexity Across KQ1 (iCAT_SR)

In addition to categorizing the intervention characteristics by intervention activity target, we also rated intervention complexity across intervention types (eg, staff only, patient and staff only) (Table 7). As a reminder, our team assessed studies using iCAT domains that were most relevant to the purpose of this systematic review.^26^ The domains that we used to assess intervention complexity included number of activities, number of actions, number of organization categories, degree of tailoring, degrees of interactions, and nature of the causal pathway. Broadly, across all KQ1 studies, many interventions included more than 1 active component with intervention actions directed at changing more than 1 HCW behavior. For example, Appelhof et al^39^ tested the BEYOND-II study for young-onset dementia that included 2 active components: staff education and a 5-step care program to manage distress behaviors. The BEYOND-II intervention aimed to (1) increase HCW ability to work in multidisciplinary teams, (2) train HCWs to design, implement, and evaluate tailored treatment plans for residents, and (3) reduce resident distress behaviors.

In addition, many interventions included a high level of interaction between intervention activities. The Appelhof et al study is an example of a study judged to have a high level of interaction between activities because the steps in the care program to reduce resident distress behaviors were interdependent. As part of the care program, staff observed residents to detect distress behaviors, nurses analyzed these observations to identify unmet needs, and then nurses, physicians, and psychologists met in a multidisciplinary case conference to develop a tailored treatment plan for each resident. Staff then evaluated whether the care plan reduced distress behaviors; if distress behaviors were not reduced, the process was repeated until the team developed a treatment plan that mitigated distress behaviors.

Tested interventions were also fairly flexible indicated by moderate to high degrees of tailoring, often through individualized treatment plans (eg, Appelhof, 2019^39^). Generally, we assessed studies with more intervention targets to also have higher degrees of tailoring. Interventions displayed the least amount of complexity in the nature of the causal pathways. Specifically, most interventions acted on a clear and short-term causal pathway between the intervention and outcome; only 2 interventions were rated as having a causal pathway that included 3 or more steps. For example, the BEYOND-II intervention was assessed to have a short, linear causal pathway because the treatment plans were hypothesized to have a direct impact on reducing distress behaviors by addressing unmet needs.^39^ On the other hand, the social interaction intervention arm examined in a study by Ballard et al^57^ was judged to have a more variable, longer causal pathway because staff received education about how to implement social activities to enhance resident interactions with staff, family, and volunteers in an effort to reduce distress behaviors. The causal pathway between staff education about social activities and impacts on distress was determined to be somewhat variable because social interactions do not directly address all unmet needs of residents displaying distress behaviors.

The intended intervention target and the number of targets influenced how complex the interventions were. Among patient-only interventions, levels of complexity were lower across all domains, except for degree of tailoring and degree of interaction. For interventions focused only at the staff level, interventions were slightly more complex than patient-only interventions, but less complex than interventions with more than 1 target. One notable exception to this observation was degree of tailoring, which was lower generally among staff-only interventions than interventions in other component areas, including patient-only interventions. Interventions in the patient and staff and the patient and staff and environment groups were fairly complex across all domains. We observed the most complexity in the domains of number of actions, degree of tailoring, and degree of interactions. Compared with single-target interventions, the multi-target interventions were slightly more complex in the nature of the causal pathway.

Table 7 Intervention Complexity (Assessed by iCAT_SR)

Study | Study Design | Number of Activities | Number of Actions | Number of Organization Categories | Degree of Tailoring | Degree of Interactions | Nature of the Causal Pathway
Patients Only
Cohen-Mansfield 2007^54^ | Cluster-randomized trial
Cohen-Mansfield 2012^50^ | Cluster-randomized trial
Eritz 2016^59^ | Cluster-randomized trial
Health Care Workers Only
Deudon 2009^51^ | Cluster-randomized trial
Fukuda 2018^41^ | Cluster-randomized trial
Leone 2012^61^ | Cluster-randomized trial
Livingston 2019^38^ | Cluster-randomized trial
Teri 2005^56^ | Cluster-randomized trial
Testad 2016^43^ | Cluster-randomized trial
Health Care Workers and Patients
Appelhof 2019^39^ | Stepped-wedge randomized trial
Ballard 2018^40^ | Cluster-randomized trial
Ballard 2016^57^ | Cluster-randomized trial (factorial)
Chapman 2007^53^ | Cluster-randomized trial
Chenoweth 2014-PCC^46^ | Cluster-randomized trial
Chenoweth 2009^52^ | Cluster-randomized trial
Fossey 2006^55^ | Cluster-randomized trial
Moniz-Cook 2017^62^ | Cluster-randomized trial
Kirkham 2020^37^ | Stepped-wedge randomized trial
Klapwijk 2018^33^ | Cluster-randomized trial
Kovach 2006^58^ | Cluster-randomized trial
Lichtwarck 2018^42^ | Cluster-randomized trial
Mork Rokstad 2013-DBM^60^ | Cluster-randomized trial
Mork Rokstad 2013-PCC^60^ | Cluster-randomized trial
Rapp 2013^49^ | Cluster-randomized trial
Stensvik 2022^34^ | Cluster-randomized trial
Van de Ven 2013^48^ | Cluster-randomized trial
Zwijsen 2014^45^ | Cluster-randomized trial
Health Care Workers, Patients, and Environment
Galik 2015^44^ | Cluster-randomized trial
Galik 2021^35^ | Cluster-randomized trial
Resnick 2021^36^ | Cluster-randomized trial

Notes. Grey = unable to assess; darker blue = more complex.

Number of activities = # of active, independent components, eg, staff training & patient assessment; number of actions = # of actions/behaviors performed by intervention recipients which the intervention is trying to change, eg, multidisciplinary case conferences & medication reviews; number of organization categories = # of organization categories directly engaged by the intervention, eg, providers, nurses, administrative staff; degree of tailoring = amount of tailoring allowed across sites or individuals in applying the intervention, eg, choice of assessment tools, menu of training topics; degree of interactions = interdependency between intervention activities, eg, earlier intervention activities necessary to complete later ones; nature of causal pathway = relationship of steps between intervention and outcome, eg, duration from intervention to expected outcomes.

### VA-Specific Studies

We identified 5 articles that addressed VA-specific interventions.^47,85–88^ All 4 were program evaluations of the Staff Training in Assisted Living Residences (STAR)-VA program that had been implemented in VA Community Living Centers (CLCs).^56^ Two articles reported on patient outcomes and staff feedback on the program after implementation with 71 Veterans,^47,56,86^ 1 reported outcomes from 302 Veterans from 71 CLCs,^85^ 1 compared use of as-needed psychotropic medications between 229 STAR-VA cases and 1,163 matched comparison cases from CLCs that did not implement STAR-VA,^88^ and 1 evaluated staff injury after STAR-VA training.^87^

In response to limited use of evidence-based nonpharmacologic interventions to address behavioral symptoms impacting the quality of life of Veterans living with dementia, the VA’s Office of Mental Health and Suicide Prevention (OMHSP) adapted the STAR program for implementation in Community Living Centers (CLC) to create STAR-VA.^89^ STAR-VA is a manualized, interdisciplinary psychosocial intervention led by a behavioral coordinator (BC) and registered nurse (RN) champion team. BCs are either psychologists, psychiatric mental health nurse practitioners, or psychiatrists. After attending a 3-day intensive workshop, followed by a 6-month case-focused, competency-based mentorship period to ensure fidelity to the intervention, the BC-RN team assists CLC staff to operationalize 4 inter-related components: (1) develop realistic expectations of a Veteran’s needs, based on understanding of how major neurocognitive disorders influence communication and behavior; (2) engage in effective communication approaches, including a technique known as listen with respect, comfort, and re-direct; (3) identify and change activators to and consequences of targeted challenging behaviors; and (4) increase frequency of personally relevant and meaningful pleasant events consistent with the person’s current preferences.

The process of delivering these components is highly individualized to each Veteran by using a structured assessment, individualized goal setting, and care planning approach to operationalize the core components. The intervention uses the theory of person-environment fit^90^ and social learning theory.^91^ Importantly, these reductions in frequency and severity of targeted behaviors were clinically significant. For example, in 1 analysis (N = 302 Veterans), the average target frequency of behavior was reduced from 3-6 times per week to 1-2 times per week.^85^ This same analysis found a reduction in agitation as measured by the CMAI of −2.6 (−10.2% change; p < 0.001). Similarly, an earlier analysis of data from 71 Veterans noted a 27.3% reduction in CMAI from 28.5 (SD = 6.6) to 20.8 (SD = 4.8) with a p < 0.0001.^86^ Moreover, implementation of STAR-VA resulted in an average reduction in “as needed” psychotropic medication use of 0.92 doses per month (95% CI [−1.82, −0.02]) compared to no reduction in matched CLC controls. Staff feedback on the program in these evaluations was generally positive.^47,86^ In the evaluation of the STAR-VA on staff injury due to assault, a reduction was noted in the year after training (p = 0.04), but rose again in the subsequent year.

Considering the key components of STAR-VA, we see a similar intervention complexity to other identified multi-level interventions (eg, those that target both HCW and patient management). Specifically, it features multiple intervention components requiring multiple actions of the involved health care team with significant tailoring to individual patients. Moreover, the interaction between the described components is significant (eg, using effective communication approaches could contribute to increasing frequency of personally relevant and pleasant events).

## KEY QUESTION 2 TRANSITIONS AMONG HEALTH CARE SETTINGS

### Key Points

- Two studies evaluated patient distress behaviors during or around a transition from 1 residential setting to another residential setting that was engineered to provide a more supportive environment and which required changes in HCW responsibilities and/or workflow patterns.
- One study of 116 patients relocated to a newly built facility with improved features (eg, improving lighting, access to indoor ambulation) found a significant reduction in distress behaviors as measured by NPI among the 14 residing in special care units for patients with advanced dementia and no change in the other 112 patients. The second study found no change in “negative affect or inappropriately engaged.”
- We did not identify any eligible studies that evaluated interventions focused on transitions from 1 health care setting to another (eg, hospital to home).

### Intervention Characteristics

We identified 2 studies that met inclusion criteria to address patient distress behaviors during or around a transition in location.^76,77^ In both studies, patients were transitioned from 1 residential setting to another residential setting that was engineered to provide a more supportive environment. We found no studies addressing distress behavior management during transitions from inpatient settings to long-term care or inpatient/long-term care to home.

Neither study referenced an underlying theory, and only the Australian study included a component of intervention fidelity through the mention of a manualized approach. Using the definitions for iCAT criteria, these interventions were relatively simple compared with interventions in KQ1, including only 1 activity (move to a different setting), a single target (the patient), and with no^76^ to moderate^77^ levels of tailoring. However, in the Australian study, the intervention was directed to both patients and home care staff who were expected to change how they engaged with the patients.

### Patient-Level Outcomes

The first relevant study^76^ was conducted in France and evaluated behavioral and psychiatric symptoms changes among 116 residents with dementia who were relocated to a newly built facility featuring improving lighting, access to indoor ambulation, and outdoor spaces for ambulation and leisure. Of the 116 patients, 102 resided in regular units and 14 in special care units that were dedicated to patients with Alzheimer’s disease. Distressed behaviors, as measured by the NPI-NH, were significantly reduced among residents in the special care units at 4 weeks (MD = −10.8, p < 0.001) and 12 weeks (MD = −14.08, SE = 2.9, p < 0.001). In contrast, there was no decrease in symptoms for those in regular units (MD at 12 weeks = −0.8, p = 0.45). The interaction between time and unit type was significant at week 4 (95% CI [−15.6, −3.1]) and week 12 (95% CI [−19.5, −6.8]). This study was considered at moderate risk of bias due to lack of information about dropouts and missing data.

A second study^77^ based in Australia measured behaviors of 55 nursing home residents with moderate-to-severe dementia before and after they were relocated from an outdated facility to a newly built setting made of 5 cottages designed specifically for the needs of 15 patients with dementia per cottage and intended to be “home-like.” In addition to the location change, staff working with residents also received a 1-week training workshop focused on engaging residents with life-skill activities. Resident distress measured by observer determination of “negative affect or inappropriately engaged” was analyzed for 43 residents with complete data and no significant difference was found in distress over 3 time points (before the transition, after the transition but before the training, and after the training). This study was considered at high risk of bias due to imbalance in disease burden between intervention and control groups, high dropout rate, new replacement participants added after study initiation, and intervention deviations.

## KEY QUESTION 3 INPATIENT MENTAL HEALTH SETTINGS

### Key Points

- Two primarily staff-focused interventions were evaluated across 3 articles.
- A theoretically driven, multifaceted intervention with 10 packaged activities (eg, Safewards) was found to reduce the rate of conflicts per shift by 15% (risk ratio [RR] = 0.85, 95% CI [0.76, 0.94]) and the rate of containment events by 26.4% (RR = 0.77, 95% CI [0.66, 0.90]). A second evaluation of a single-site staff education program with ongoing monitoring reduced the average number of aggressive incidents towards peers or objections by 6 to 2.

### Intervention Characteristics

Two interventions (3 studies) focused on staff-facing activities in the inpatient mental health treatment setting.^78–80^ In both interventions, staff education was a key component. In a randomized trial^78^ of 31 acute inpatient mental health wards from 15 British hospitals, a theoretically driven (eg, Safewards), multifaceted intervention with 10 packaged activities (eg, de-escalation model, access to distraction and sensory tools for patients, standards of behavior for staff) aimed at staff training was evaluated with respect to the impact on staff-patient conflict and containment.^78^ Both interventions were fairly complex per iCAT standards. They were staff-focused, multi-component interventions that were moderately tailored to address resident and staff behavior.

### Patient-Level Outcomes

Conflict was measured by charge nurse observation per shift using a checklist and included 22 types of conflict events including verbal aggression, substance use, and self-harm attempts; containment was similarly measured and accounted for 8 types of containment (eg, coerced medication, restraints). At 16 weeks, rate of conflicts was reduced by 15% in the intervention arm per shift (RR = 0.85, 95% CI [0.76, 0.94]) and rate of containment events was reduced by 26.4% (RR = 0.77, 95% CI [0.66, 0.90]). Notably, data collection for the primary outcomes was low due to <50% of data collection forms being submitted; sensitivity analyses showed that missingness was slightly greater in the control group (OR = 0.87, 95% CI [0.74, 1.03]). A later program evaluation^79^ conducted a cross-sectional survey of staff after the government-funded implementation of Safewards across 7 self-selected health services in Australia. After 9-12 months of implementation, 76 staff reported a positive impact of the intervention on verbal conflicts (42% usually or always) and physical conflicts (34% usually or always). Fifty-four percent of staff reported usually or always feeling “positive about being on the unit,” and 38% reported feeling safer. This program evaluation was considered at serious risk of bias largely due to the optional nature of the staff survey.

A second study evaluated the effect of a staff education program that emphasized communication skills, environmental changes, incident reporting, medication management, and resident activities in a community-based, long-term 170 bed neurobehavioral rehabilitation program setting.^80^ Staff received skills assessments, a day-long training, in-service training, and ongoing monitoring to improve staff self-efficacy. At 15 months among 267 patients with a minimum stay of 5 days, the average number of aggressive incidents toward peers or objects per month per quarter had been reduced by 77%, from 6 to 2. This study was considered at serious risk of bias largely due to high turnover of patients, lack of blinded outcomes assessment, and lack of consideration of confounding.