# METHODS

## REGISTRATION AND REVIEW

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (CRD42023402760 (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=402760)). A draft version of this report was reviewed by external peer reviewers; their comments and author responses are located in the Appendix.

## KEY QUESTIONS AND ELIGIBILITY CRITERIA

The following key questions were the focus of this review:

Key Question 1 | What is the effect of health care team-focused interventions designed to manage persistent or recurrent distress behaviors among older adults in long-term residential or inpatient health care settings on patient, staff, and utilization outcomes?
Key Question 2 | What is the effect of health care team-focused interventions designed to manage persistent or recurrent distress behaviors among older adults during transitions between health care settings on patient, staff, and utilization outcomes?
Key Question 3 | What is the effect of health care team-focused interventions designed to manage persistent or recurrent distress behaviors among older adults in the context of inpatient mental health settings on patient, staff, and utilization outcomes?

Study eligibility criteria are shown in the table below. Overall, we focused on interventions intended to improve health care staff knowledge and behaviors related to distress behavior management. We did not include patient-directed interventions (eg, providing patient-tailored background music). An analytic framework that illustrates the relationship between key questions and eligible interventions and outcomes is provided in the Appendix.

Eligibility Criteria
| Inclusion | Exclusion
Population | Older adults (≥ 50 years of age) in residential, long-term, inpatient health care settings or who are transitioning between hospital to these settings or to home and who are at elevated risk of persistent or recurrent distress behaviors in health care settings associated with underlying conditions such as neurocognitive disorders (eg, dementia), mental health disorders (eg, serious mental illness, psychosis, PTSD, substance use disorders), and/or other chronic medical illnesses; Eligible studies must include at least 75% of participants aged ≥ 50 years; Patients could be those identified to be at-risk OR those already displaying disruptive behaviors | Patients not currently in residential or inpatient settings (eg, home-based care, outpatient); Peri-operative or ICU patients; Studies with populations < 75% aged ≥ 50 years; Patients with primary diagnosis of delirium; Intoxicated patients or patients in acute substance withdrawal; Pediatric population or populations with < 75% patients < 50 years
Intervention | Staff- or health care unit-focused approaches to build capacity, knowledge, behaviors, or skills intended to reduce or prevent distressed and/or disruptive behaviors among a population of older adults in indicated health care settings; Intervention could involve staff or clinic-facing interventions that focus on optimizing facility staffing, staff training, and education, and/or developing and strengthening staff competencies as they relate to managing disruptive behaviors; Intervention must be primarily targeted at the health care providers or unit (eg, team, clinical service) as the primary point of deployment that involves a change in the way care is delivered; Interventions must specify a primary intent to reduce disruptive and/or distressed behaviors (or have such behaviors as a primary outcome); Interventions could include electronic health record components that involve staff interaction or recognition of at-risk patients | Interventions that target the patient as the level of deployment only and do not involve staff or the health care unit employed by a health care system; Interventions that only involve staff for training of the delivery of an individual patient-level therapy for symptom management (eg, pet therapy, music therapy); Interventions focused on management of symptoms of chronic condition only or which mention disruptive behavior as a minor focus of the intervention; Pharmacologic interventions
Comparator | Any or none | NA
Outcomes | Patient outcomes: Mental and/or medical symptom improvement, improvement or management of disruptive behavior (to include neuropsychiatric symptoms such as agitation, aggression), patient safety, quality of life; Staff outcomes: Morale, provider/staff satisfaction, provider/staff safety, turnover, staff competencies/skills, or staff self-efficacy as they relate to handling disruptive behaviors; Utilization outcomes: Length of stay in acute care hospital or nursing home settings, timeliness of discharge, hospital re-admissions, overall costs of care | Studies that do not explicitly state the primary intent to be the improvement of disruptive behaviors must have disruptive behaviors as primary outcome (though data were collected on other secondary outcomes of interest); Neuropsychiatric symptoms such as apathy, depression, delusions, hallucinations, delirium
Timing | Any | NA
Setting | Inpatient medicine, inpatient mental health, residential care/nursing homes, and transitional care, including from hospital or nursing home to community-based or family caregiving | Outpatient, home-based care settings, nonclinical group home settings, emergency departments
Study Design | Randomized trials, nonrandomized trials, controlled before-after studies, interrupted time-series studies or repeated measures studies, retrospective/prospective cohort studies, case-control studies, program evaluations | Patient-level case studies/series, systematic reviews, organizational case studies
Publication Types | Full publication in a peer-reviewed journal | Letters, opinion pieces, editorials, reviews, dissertations, meeting abstracts, and protocols without results; Pilot studies (for KQ1 only)
Years | December 2002-present
Language | No limits | NA
Country | Organization for Economic Co-operation and Development countries (Australia, Austria, Belgium, Canada, Chile, Colombia, Costa Rica, Czech Republic, Denmark, Estonia, Finland, France, Germany, Greece, Hungary, Iceland, Ireland, Israel, Italy, Japan, Korea, Latvia, Lithuania, Luxembourg, Mexico, Netherlands, New Zealand, Norway, Poland, Portugal, Slovak Republic, Slovenia, Spain, Sweden, Switzerland, Turkey, United Kingdom, United States) | Non-OECD countries

Abbreviations. ICU=intensive care unit; PTSD=posttraumatic stress disorder.

## SEARCHING AND SCREENING

To identify articles relevant to the key questions (KQs), a research librarian searched Ovid MEDLINE, Elsevier Embase, and Ovid PsycInfo from December 2002 through December 2022 using terms for setting (residential, transition of care), inpatients with mental illness, older adults, older adult inpatients with mental illness, distressed or disruptive behavior (see Appendix for complete search strategies). Additional citations were identified from hand-searching reference lists and consultation with content experts. We limited the search to published and indexed articles involving human subjects and OECD countries. Study selection was based on the eligibility criteria described above. Titles, abstracts, and full-text articles were reviewed by 2 investigators. All disagreements were resolved by consensus or discussion with a third reviewer.

## DATA ABSTRACTION AND ASSESSMENT

We approached the abstraction and synthesis of each KQ separately, as each KQ focuses on distinct health care settings with different staffing and team dynamics. We expected KQ1 to yield the largest number of available studies based on a recent systematic review conducted by AHRQ^25^ that included 19 randomized controlled trials (RCTs) and was focused solely on patients with dementia living in nursing home and assisted living settings.

We synthesized available studies following a best-evidence approach. Specifically, we prioritized synthesis of studies with more rigorous designs (eg, randomized trials, nonrandomized trials, controlled before-after, interrupted time series) over less rigorous designs (eg, retrospective or prospective cohort studies, program evaluations). If we identified a sufficient number of randomized trials, we prioritized these over all other designs. Because this project is intended to inform VA policy and decision-making, we also included all VA-specific studies regardless of design for contextualization and comparison. If VA studies used less rigorous designs, we included them descriptively but did not conduct a formal risk of bias assessments or incorporate them into certainty of evidence assessments. In addition, given the existence of a prior high-quality systematic review relevant to this topic,^25^ we abstracted descriptive information about primary studies from those reviews with up to 20% over-reading to verify accuracy of data.

Effect information and population, intervention, and comparator characteristics were abstracted for all prioritized studies. From these studies, we also abstracted key intervention characteristics and evaluated intervention complexity using a modified iCAT-SR tool to inform future intervention implementation.^26^ We report intervention labels such as “person-centered” based on author description in published papers. To group the prioritized studies conceptually for analysis, we considered multiple approaches and sought input from our technical expert panel and operational partner to identify a meaningful approach that aligns with the way that people caring for patients with distress behaviors group and label patient care activities. Given the complexity and multi-component nature of the interventions, we were unable to group for analysis by any 1 specific intervention activity (eg, antipsychotic medication review). Instead, we grouped studies by current clinical practice approaches adapted from the Alzheimer’s Association Dementia Care Practice Recommendations.^27^ The Association developed these recommendations to define quality of care across all care settings for patients with dementia. Of the 10 total Association recommendations, we identified 8 that we determined were most relevant to the care of older adults experiencing distress to categorize interventions. For each of these 8, we developed tailored definitions for operationalization and mapped each adapted recommendation to the level at its intended impact (ie, patient, staff, environment/setting) (listed and defined in Appendix). Given the complexity of interventions in the included studies, many interventions targeted more than 1 level. Therefore, our final grouping categories included HCW-focused-only, patient-only (interventions designed to change HCW behaviors and interactions with patients), HCW-/patient-focused, and patient-, HCW-, and environment-focused interventions. We did not include any environment-only studies as these would not meet our eligibility criteria of requiring a health care team or HCW focus. We then abstracted intervention characteristics for all studies.

Information abstracted included a description of the intervention, setting, target patient population, components of the intervention, dose, who delivered the intervention, the disciplines of staff receiving the intervention, the intervention delivery mode, and the underpinning theories. Then, descriptions of interventions were reviewed across included studies and key intervention activities were identified. Intervention activities were mapped to the adapted Alzheimer’s Association practice recommendation categories by 1 reviewer who referenced the original study as needed. A second reviewer corroborated these decisions. Discrepancies were resolved through discussion and consensus between the 2 reviewers (MSB, KMG).

The internal validity (ie, risk of bias) of each prioritized study was rated using Cochrane risk of bias tools for randomized trials^28^ or other intervention study designs.^29^ All data abstraction was first completed by 1 reviewer and then checked by another; disagreements were resolved by consensus or discussion with a third reviewer (see Appendix for risk of bias ratings). Risk of bias assessment was completed independently by 2 reviewers and disagreements were resolved by consensus.

## SYNTHESIS

When synthesizing evidence for KQ1, we prioritized studies judged as moderate or low risk of bias. When at least 3 studies with the same outcome were available, we synthesized results using 3-level random-effects models that accounted for clustering of observations within studies as well as clustering of comparisons within studies in the case of 3 or more treatment groups. For analyses with fewer than 20 studies, we used the Knapp-Hartung adjustment to better account for uncertainty in heterogeneity estimates. If meta-analysis was not feasible, we summarized available evidence narratively.

When meta-analysis was possible, bias-adjusted standardized mean differences (SMDs) were used for continuous outcomes and odds ratios (ORs) for binary outcomes. The random effects model used to estimate the overall/pooled effect accounted for shared variance of samples within studies and shared variance among multiple comparisons within studies where applicable. For cluster-randomized trials and stepped-wedge designs, we incorporated a design effect into effect size calculation using intraclass correlation coefficients (ICCs).^30^ If ICCs were not reported, we used the average of ICCs reported by other studies of the same outcome; if no ICCs were available, an ICC of 0.10 was assumed. If measured constructs were considered not sufficiently conceptually similar, outcome data were synthesized separately.

Heterogeneity was assessed using visual inspection and 95% prediction intervals. Publication bias was assessed using funnel plots (when there were > 10 studies) and Begg’s or Egger’s regression statistics. Meta-analyses were conducted using the metafor package^31^ for R (R Foundation for Statistical Computing, Vienna, Austria).

### Strength of Evidence

After synthesizing available evidence, we rated the strength of evidence for prioritized outcomes (those outcomes identified by the stakeholders as critical to decision-making with sufficient data for synthesis). Assessment of strength of evidence was guided by the Grading of Recommendations Assessment, Development and Evaluation (GRADE) approach,^32^ which requires assessment of 4 domains: risk of bias, consistency, directness, and precision. Additional domains to be used when appropriate are dose-response association, impact of plausible residual confounders, strength of association (magnitude of effect), and publication bias. Domains were considered qualitatively, and a summary rating was assigned after discussion by 3 investigators (high, moderate, or low). When high, moderate, or low ratings were impossible or imprudent to make, evidence was considered insufficient to draw conclusions.