# BACKGROUND

Older adults with comorbid medical disorders (eg, dementia, serious mental illness, multiple chronic medical conditions) may experience an increased prevalence of behavioral and psychological symptoms. Exacerbation of these symptoms is likely due to vulnerability to environmental factors such as under- or over-stimulation, or unmet medical, physical, emotional, and social needs that may unintentionally be reinforced by staff or care routines. These behavioral and psychological symptoms, in the context of receiving care across health care settings, can be considered as manifestations of patient distress and may be uncomfortable for both patients and their paid caregivers. Patient distress and associated behaviors can affect patient quality of life, care provision, cost of care, or transition to community-based care settings.^1–3^

Among patients with dementia, 75% exhibit at least 1 neuropsychiatric symptom.^4^ While mental illness and other cognitive disorders among older adults, including serious mental illness (SMI), substance use disorders (SUD), and intellectual and developmental disabilities (IDD), are less well researched, distress behaviors are also prevalent with these conditions. For example, in 2004, among nursing home residents in the VA health care system, 66% of Veterans with SMI expressed verbal “disruption,” nearly 30% expressed physical aggression, and 58% expressed inappropriate behavior.^5^ Distress behaviors can cause significant challenges to the ability of health care systems generally and for clinical providers in particular to deliver care using traditional, clinician-focused strategies (eg, close monitoring, new treatment plans),^6^ as these strategies tend to prioritize diagnostic procedures, close monitoring, and delivery treatments within the context of short stays.^7^ These challenges can lead to staff burnout.^8,9^ In order to better address the patient needs underlying recognized patient distress behaviors and better prepare health care teams to meet these patient needs in a productive and safe work environment, it is imperative that health systems develop high-quality approaches for patients with these complex needs.^10^

Existing strategies to manage distress behaviors are largely ineffective and considered not patient centered. For example, antipsychotic medications have been used to manage behaviors perceived as disruptive by health care teams.^11,12^ Between 2011 and 2019, 80% of publicly funded long-stay nursing home residents in the United States received an antipsychotic prescription.^13^ However, reliance on these medications is off-label and not always effective to address behavioral disturbances,^14^ and some medications are known to have substantial adverse effects, including an increased risk of death.^15^ Historically, restraints are another ineffective approach used to prevent wandering and falls among older adults in institutional settings.^16^ However, the use of restraints is still relatively high, especially for older adults with dementia.^17^ Given ethical concerns about restricting individual autonomy and the potential harms, advocates increasingly view physical restraints as an untenable approach to manage distress behaviors.^18^ For example, the Joint Commission and the Alzheimer’s Association recently announced a collaboration to improve quality and safety in skilled nursing facilities through evidenced-based practice recommendations.^19,20^

Effective, patient-centered nonpharmacologic approaches are critically needed to better support patients who are at increased risk for distress and related behaviors through centering care provision and accommodation on the patient. Interventions primarily focused on changing health care worker (HCW) skills, patient interactions, and team roles are particularly compelling to promote safe, person-centered, and positive systemic change. For example, Staff Training in Assisted Living Residences (STAR-VA) is a training program for staff working in VA Community Living Centers that aims to support teams in understanding and managing distress behaviors among residents with dementia via a team-based, behavioral, problem-solving approach. STAR-VA helps teams have realistic expectations of individuals with dementia, communicate effectively, and use the ABC model (identify and change activators and consequences to specific behaviors, and integrate person-centered pleasant events into daily care).^21^

Despite integration of individual patient-level nonpharmacologic approaches into recent guidelines for the care of older adults with dementia, interventions primarily focused on HCWs (eg, improving HCW skills and knowledge or adjusting workflow patterns or team roles) have received limitation attention. In addition, while patients with SMI and other psychiatric disorders are overrepresented in residential long-term care settings,^22–24^ little is known about the use of these strategies among this high-risk population. The goal of this systematic review is to evaluate the effect of interventions designed to address patient distress behaviors, focusing on HCW-focused interventions (eg, optimal staffing, staffing education/training). For this review, we focus on interventions to ameliorate patient distress leading to behaviors such as physical or verbal aggression, repeated vocalizations, yelling, pacing, wandering, hoarding, handling objects unsafely, sexual disinhibition, psychosis, disengagement, or apathy.

This review was nominated by the VA Office of Mental Health and Suicide Prevention to inform work being done by the VHA Interoffice of Care for Patients with Complex Problems Steering Committee to support health care delivery for Veterans with distress behaviors.