# Appendix

## SEARCH STRATEGIES

Librarian searcher: Sarah Cantrell, MLIS; Duke University Medical Center Library & Archives, Duke University School of Medicine

Peer review of search conducted by: Samantha Kaplan, PhD, MLS; Duke University Medical Center Library & Archives, Duke University School of Medicine

Database: MEDLINE (via Ovid)

Search date: 12/14/2022

note: Ovid MEDLINE(R) ALL 1946 to December 13, 2022

| Search Set | Search Statement | Results
1 | setting – residential | residential facilities/ or exp assisted living facilities/ or exp long-term care/ or exp homes for the aged/ or exp nursing homes/ or exp skilled nursing facilities/ or exp intermediate care facilities/ or (“nursing home” or “nursing homes” or “assisted living” or “homes for the aged” or “home for the aged” or “homes for the elderly” or “home for the elderly” or snf or “skilled nursing facility” or “skilled nursing facilities”).ti,ab. or (residential adj3 (care or healthcare or treat* or therap*)).ti,ab. or ((residential or rehab*) adj3 facilit*).ti,ab. or ((home or homes or facility or facilities or house or houses or housing) adj3 (aged or elderly or geriatric or “old adult” or “old adults” or “older adult” or “older adults” or “old person” or “older person” or “old people” or “older people” or senior or seniors)).ti,ab. or ((longterm or “long term” or extended) adj3 (care or healthcare or facilit*)).ti,ab. | 128,335
2 | setting – transition of care | continuity of patient care/ or exp “hospital to home transition”/ or exp patient transfer/ or exp transitional care/ or (continuity adj3 (care or healthcare)).ti,ab. or ((transition or transitions or transitioned or transitioning or transitional) adj3 (care or healthcare or home or homes or house or houses or housing)).ti,ab. or ((“patient transfer” or “patient transfers”) adj3 (residence or residences or residential or home or house or homes or houses)).ti,ab. or (hospital* adj3 (residence or residences or residential or home or house or homes or houses) adj3 (transition or transitions or transitioned or transitioning or transitional)).ti,ab. or ((home or home-based) adj3 (“primary care” or “primary healthcare”)).ti,ab. | 45,337
3 | Inpatients w/mental illness | ((inpatient* or in-patient* or (hospital* adj2 patient*)) adj4 (“mental health” or “mental illness” or “mental illnesses” or “mentally ill” or psychiatric or neuropsychiatric)).ti,ab. | 17,802
4 | Older adults | exp middle aged/ or exp aged/ or exp “health services for the aged”/ or (aged or aging or “older adult” or “older adults” or “old person” or “older person” or “old people” or “older people” or “old folk” or “old folks” or “older folk” or “older folks” or elder or elders or elderly or senior or seniors or geriatric or geriatrics or retired or retiree or retirees).ti,ab. | 6,122,348
5 | older adult inpatients w/mental illness | 3 and 4 | 7,527
6 | Combining settings | 1 or 2 or 5 | 177,096
7 | Disruptive behavior | exp psychological distress/ or exp psychomotor agitation/ or exp problem behavior/ or violence/ or exp impulsive behavior/ or anger/ or exp hostility/ or exp wandering behavior/ or ((disrupt* or neuropsych* or problem or problematic or challenging or danger* or violen* or aggress* or distress* or uncooperative or “not cooperative” or anger or angry or hostil* or impulsive*) adj6 (behav* or demeanor or conduct or action or actions or symptom or symptoms)).ti,ab. or ((abus* or nonsens* or inappropriate* or expressive) adj2 (language or speech)).ti,ab. | 188,857
8 | concept combination | 6 and 7 | 4218
9 | date limit 2000 - present | limit 8 to da=20000101-20231231 | 3530
10 | study design exclusion | 9 not (case reports or editorial or letter or comment or congress).pt. | 3,363

Database: Embase (via Elsevier)

search date: 12/14/2022

note: Search from the Results page

| Search Set | Search Statement | Results
1 | setting – residential | ‘assisted living facility’/exp OR ‘long term care’/de OR ‘home for the aged’/exp OR ‘nursing home’/exp OR (‘nursing home’ OR ‘nursing homes’ OR ‘assisted living’ OR ‘homes for the aged’ OR ‘home for the aged’ OR ‘homes for the elderly’ OR ‘home for the elderly’ OR snf OR ‘skilled nursing facility’ OR ‘skilled nursing facilities’):ti,ab OR (residential NEAR/3 (care OR healthcare OR treat* OR therap*)):ti,ab OR ((residential OR rehab*) NEAR/3 facilit*):ti,ab OR ((home OR homes OR facility OR facilities OR house OR houses OR housing) NEAR/3 (aged OR elderly OR geriatric OR ‘old adult’ OR ‘old adults’ OR ‘older adult’ OR ‘older adults’ OR ‘old person’ OR ‘older person’ OR ‘old people’ OR ‘older people’ OR senior OR seniors)):ti,ab OR ((longterm OR ‘long term’ OR extended) NEAR/3 (care OR healthcare OR facilit*)):ti,ab | 271,864
2 | setting – transition of care | ‘hospital to home transition’/exp OR ‘transitional care’/exp OR (continuity NEAR/3 (care OR healthcare)):ti,ab OR ((transition OR transitions OR transitioned OR transitioning OR transitional) NEAR/3 (care OR healthcare OR home OR homes OR house OR houses OR housing)):ti,ab OR ((‘patient transfer’ OR ‘patient transfers’) NEAR/3 (residence OR residences OR residential OR home OR house OR homes OR houses)):ti,ab OR (hospital* NEAR/3 (residence OR residences OR residential OR home OR house OR homes OR houses) NEAR/3 (transition OR transitions OR transitioned OR transitioning OR transitional)):ti,ab OR ((home OR home?based) NEAR/3 (‘primary care’ OR ‘primary healthcare’)):ti,ab | 33,684
3 | inpatients w/mental illness | ((inpatient* OR in?patient*) NEAR/4 (‘mental health’ OR ‘mental illness’ OR ‘mental illnesses’ OR ‘mentally ill’ OR psychiatric OR neuropsychiatric)):ti,ab OR (hospital* patient* NEAR/4 (‘mental health’ OR ‘mental illness’ OR ‘mental illnesses’ OR ‘mentally ill’ OR psychiatric OR neuropsychiatric)):ti,ab; OR (hospital* NEAR/2 patient*)) | 33,489
4 | older adults | ‘middle aged’/exp OR ‘aged’/exp OR ‘elderly care’/de OR ‘geriatric care’/exp OR (aged OR aging OR ‘older adult’ OR ‘older adults’ OR ‘old person’ OR ‘older person’ OR ‘old people’ OR ‘older people’ OR ‘old folk’ OR ‘old folks’ OR ‘older folk’ OR ‘older folks’ OR elder OR elders OR elderly OR senior OR seniors OR geriatric OR geriatrics OR retired OR retiree OR retirees):ti,ab | 5,804,962
5 | older adult inpatients w/mental illness | #3 AND #4 | 9,072
6 | combining settings | #1 OR #2 OR #5 | 310,907
7 | disruptive behavior | ‘distress syndrome’/exp OR ‘agitation’/exp OR ‘disruptive behavior’/exp OR ‘impulsiveness’/exp OR ‘anger’/exp OR ‘hostility’/exp OR ‘wandering behavior’/exp OR ((disrupt* OR neuropsych* OR problem OR problematic OR challenging OR danger* OR violen* OR aggress* OR distress* OR uncooperative OR ‘not cooperative’ OR anger OR angry OR hostil* OR impulsive*) NEAR/6 (behav* OR demeanor OR conduct OR action OR actions OR symptom OR symptoms)):ti,ab OR ((abus* OR nonsens* OR inappropriate* OR expressive) NEAR/2 (language OR speech)):ti,ab | 288,415
8 | concept combination | #6 AND #7 | 7616
9 | date limit 2000 - present | #8 AND [01-01-2000]/sd | 6969
10 | study design exclusion | #9 NOT (‘case report’/exp OR ‘case study’/exp OR ‘editorial’/exp OR [editorial]/lim OR ‘letter’/exp OR [letter]/lim OR ‘note’/exp OR [note]/lim OR [conference abstract]/lim OR ‘conference abstract’/exp OR ‘conference abstract’/it) | 4,433

Database: APA PsycINFO (via Ovid)

search date: 12/14/2022

note: APA PsycINFO 1806 to December Week 1 2022

| Search Set | Search Statement | Results
1 | setting – residential | “Residential Care Institutions”/ or exp nursing homes/ or exp “nursing home residents”/ or assisted living/ or “long term care”/ or (“nursing home” or “nursing homes” or “assisted living” or “homes for the aged” or “home for the aged” or “homes for the elderly” or “home for the elderly” or snf or “skilled nursing facility” or “skilled nursing facilities”).ti,ab. or (residential adj3 (care or healthcare or treat* or therap*)).ti,ab. or ((residential or rehab*) adj3 facilit*).ti,ab. or ((home or homes or facility or facilities or house or houses or housing) adj3 (aged or elderly or geriatric or “old adult” or “old adults” or “older adult” or “older adults” or “old person” or “older person” or “old people” or “older people” or senior or seniors)).ti,ab. or ((longterm or “long term” or extended) adj3 (care or healthcare or facilit*)).ti,ab. | 45,947
2 | setting – transition of care | “Continuum of Care”/ or “client transfer”/ OR (continuity adj3 (care or healthcare)).ti,ab. or ((transition or transitions or transitioned or transitioning or transitional) adj3 (care or healthcare or home or homes or house or houses or housing)).ti,ab. or ((“patient transfer” or “patient transfers”) adj3 (residence or residences or residential or home or house or homes or houses)).ti,ab. or (hospital* adj3 (residence or residences or residential or home or house or homes or houses) adj3 (transition or transitions or transitioned or transitioning or transitional)).ti,ab. or ((home or home-based) adj3 (“primary care” or “primary healthcare”)).ti,ab. | 8,151
3 | inpatients w/mental illness | ((inpatient* or in-patient* or (hospital* adj2 patient*)) adj4 (“mental health” or “mental illness” or “mental illnesses” or “mentally ill” or psychiatric or neuropsychiatric)).ti,ab. | 18,093
4 | older adults | “older adulthood”/ or “geriatric patients”/ or “middle adulthood”/ OR (aged or aging or “older adult” or “older adults” or “old person” or “older person” or “old people” or “older people” or “old folk” or “old folks” or “older folk” or “older folks” or elder or elders or elderly or senior or seniors or geriatric or geriatrics or retired or retiree or retirees).ti,ab. | 451,157
5 | older adult inpatients w/mental illness | 3 and 4 | 2,473
6 | combining settings | 1 or 2 or 5 | 55,550
7 | disruptive behavior | “Distress”/ OR “Agitation”/ OR “Violence”/ OR “Patient Violence”/ OR “Impulsiveness”/ OR “Anger”/ OR “Anger Expression”/ OR “Hostility”/ OR “Wandering Behavior”/ OR ((disrupt* or neuropsych* or problem or problematic or challenging or danger* or violen* or aggress* or distress* or uncooperative or “not cooperative” or anger or angry or hostil* or impulsive*) adj6 (behav* or demeanor or demanour or conduct or action or actions or symptom or symptoms)).ti,ab. or ((abus* or nonsens* or inappropriate* or expressive) adj2 (language or speech)).ti,ab. | 191,082
8 | concept combination | 6 and 7 | 3509
9 | date limit 2000 - present | limit 8 to yr=“2000 -Current” | 2688
10 | limit | limit 9 to “0110 peer-reviewed journal” | 2274
11 | limit | limit 10 to (journal article or reviews) | 2111

## ANALYTIC FRAMEWORK

## STUDY CHARACTERISTICS

Refer to the main report’s reference list for full citations.

### STUDY CHARACTERISTICS FOR STUDIES RATED AS LOW OR SOME CONCERNS FOR RISK OF BIAS

### STUDY CHARACTERISTICS FOR STUDIES RATED AS HIGH RISK OF BIAS

### STUDY CHARACTERISTICS FOR STAR-VA STUDIES

## INTERVENTION CHARACTERISTICS

Refer to the main report’s reference list for full citations.

## INTERVENTION CODING DOMAINS AND OPERATIONALIZED DEFINITIONS

Coding domains are adapted from the Alzheimer’s Association Dementia Care Practice Recommendations: Dementia Care Practice Recommendations |Alzheimer’s Association (https://www.alz.org/professionals/professional-providers/dementia_care_practice_recommendations).^10^

Patient-Level | Definition
Detection and diagnosis | Mentoring/identifying for symptoms or unmet needs
Assessment and care planning | Individualized care plan development
Ongoing care for behavioral-psychological symptoms of dementia and support ADLs | Ongoing monitoring and/or evaluating effectiveness of practices and adjusting as needed
Medical management | Medication review (eg, antipsychotic medications)
Medical management | Addressing uncontrolled medical diagnoses
Medical management | Addressing uncontrolled psychological diagnoses
Staff-Level
Information, education, and support | Education programs about dementia specifically and general nonpharmacologic approaches to addressing unmet needs and managing distress behaviors
Information, education, and support | Would NOT include training on a change in process or protocol otherwise captured in other domains
Staffing | Care coordination (eg, multidisciplinary team meetings)
Staffing | Changes to team composition (eg, hiring a new discipline)
Environment
Supportive and therapeutic environments | Approaches that impact or adjust physical environment to meet patient needs
Transitions
Transitions and coordination of services | Approaches related to preparing for transitions from one care level to another

## STUDIES EXCLUDED DURING FULL-TEXT SCREENING

Citation | Exclude Reason
Allen, 2000^1^ | Ineligible population
Almutairi, 2022^2^ | Ineligible intervention
Andersen, 2017^3^ | Ineligible study design
Anonymous, 2002^4^ | Ineligible publication type
Appelhof, 2018^5^ | Ineligible outcome
Arco, 2006^6^ | Ineligible study design
Ayalon, 2009^7^ | Ineligible publication type
Bakerjian, 2020^8^ | Ineligible intervention
Beck, 2002^9^ | Ineligible intervention
Bharani, 2005^10^ | Ineligible publication type
Bhat, 2020^11^ | Ineligible population
Bielderman, 2021^12^ | Ineligible population
Bird, 2009^13^ | Ineligible intervention
Bjorkdahl, 2013^14^ | Ineligible population
Blair, 2017^15^ | Ineligible population
Boettcher, 2004^16^ | Ineligible study design
Borbasi, 2010^17^ | Ineligible publication type
Bradshaw, 2004^18^ | Ineligible population
Buisson, 2019^19^ | Ineligible study design
Burack, 2012^20^ | Ineligible study design
Burgio, 2004^21^ | Ineligible study design
Burgio, 2002^22^ | Ineligible date
Carbone, 2021^23^ | Ineligible intervention
Chao, 2005^24^ | Ineligible country
Chen, 2016^25^ | Ineligible country
Chenoweth, 2007^26^ | Ineligible study design
Chiappinotto, 2022^27^ | Ineligible intervention
Chou, 2016^28^ | Ineligible intervention
Chou, 2011^29^ | Ineligible country
Chrzescijanski, 2007^30^ | Ineligible study design
Chung, 2004^31^ | Ineligible country
Ã‡oban Arguvanli, 2015^32^ | Ineligible population
Cohen-Mansfield, 2006^33^ | Ineligible intervention
Cohen-Mansfield, 2010^34^ | Ineligible intervention
Cohen-Mansfield, 2014^35^ | Ineligible intervention
Crotty, 2004^36^ | Ineligible intervention
da Silva Serelli, 2017^37^ | Ineligible country
Dechamps, 2010^38^ | Ineligible study design
DeYoung, 2002^39^ | Ineligible study design
DiBartolo, 2013^40^ | Ineligible study design
Dichter, 2015^41^ | Ineligible study design
Dobbs, 2018^42^ | Ineligible outcome
Duinen-van den Ijssel, 2020^43^ | Ineligible outcome
Egan, 2007^44^ | Ineligible intervention
Eggermont, 2010^45^ | Ineligible intervention
Eisch, 2000^46^ | Ineligible intervention
Engst, 2004^47^ | Ineligible intervention
Fitzler, 2016^48^ | Ineligible study design
Fitzwater, 2002^49^ | Ineligible study design
Garland, 2007^50^ | Ineligible intervention
Gerdner, 2005^51^ | Ineligible intervention
Gerolimatos, 2018^52^ | Ineligible study design
Gillis, 2019^53^ | Ineligible study design
Gonzalez-Fraile, 2021^54^ | Ineligible study design
Graske, 2019^55^ | Ineligible setting
Hawranik, 2008^56^ | Ineligible intervention
Hazelhof, 2014^57^ | Ineligible intervention
Henskens, 2018^58^ | Ineligible intervention
Hicks-Moore, 2005^59^ | Ineligible intervention
Hicks-Moore, 2008^60^ | Ineligible intervention
Holle, 2015^61^ | Ineligible outcome
Holm, 1999^62^ | Ineligible date
Hong, 2011^63^ | Ineligible intervention
Hsu, 2015^64^ | Ineligible study design
Husebo, 2011^65^ | Ineligible intervention
Husebo, 2015^66^ | Ineligible outcome
Irvine, 2013^67^ | Ineligible outcome
Isaac, 2021^68^ | Ineligible study design
Jervis, 2002^69^ | Ineligible intervention
Kerssens, 2014^70^ | Ineligible intervention
Kim, 2005^71^ | Ineligible intervention
Klapwijk, 2018^72^ | Ineligible outcome
Koczy, 2011^73^ | Ineligible outcome
Kolanowski, 2011^74^ | Ineligible intervention
Koskas, 2011^75^ | Ineligible study design
Kovach, 2004^76^ | Ineligible intervention
Kramarz, 2022^77^ | Ineligible study design
Kuiper, 2009^78^ | Unable to locate full text
Landreville, 2005^79^ | Ineligible study design
Landreville, 2011^80^ | Unable to locate full text
Lamppu, 2021^81^ | Ineligible intervention
Lay, 2015^82^ | Ineligible population
Lay, 2015^83^ | Ineligible outcome
Lichtenberg, 2005^84^ | Ineligible study design
Loi, 2017^85^ | Ineligible intervention
Lykkeslet, 2016^86^ | Ineligible study design
Maidment, 2020^87^ | Ineligible outcome
Manepalli, 2009^88^ | Ineligible study design
Massaia, 2001^89^ | Ineligible intervention
McAiney, 2007^90^ | Ineligible outcome
McCreedy, 2022^91^ | Ineligible intervention
McGill, 2018^92^ | Ineligible population
Meehan, 2001^93^ | Ineligible intervention
Mickus, 2002^94^ | Ineligible date
Monette, 2008^95^ | Ineligible study design
Moniz-Cook, 1998^96^ | Ineligible study design
Morgan, 2005^97^ | Ineligible intervention
Morley, 2013^98^ | Ineligible publication type
Muniz, 2021^99^ | Ineligible intervention
O’Connell, 2020^100^ | Ineligible population
Oh, 2005^101^ | Ineligible study design
Opie, 2002^102^ | Ineligible date
Orrell, 2007^103^ | Ineligible intervention
Park, 2012^104^ | Ineligible population
Pouwels, 2019^105^ | Ineligible study design
Ray, 2017^106^ | Ineligible intervention
Resnick, 2016^107^ | Ineligible study design
Robert, 2021^108^ | Ineligible intervention
Rose, 2014^109^ | Ineligible population
Rosewarne, 1997^110^ | Ineligible date
Rota-Bartelink, 2011^111^ | Ineligible intervention
Roth, 2002^112^ | Ineligible date
Ryan, 2018^113^ | Ineligible study design
Ryden, 2000^114^ | Ineligible date
Samus, 2013^115^ | Ineligible outcome
Sanchez, 2016^116^ | Ineligible intervention
Sansone, 2000^117^ | Ineligible population
Shah, 1998^118^ | Ineligible date
Sidani, 2012^119^ | Ineligible study design
Simard, 2010^120^ | Ineligible intervention
Sloane, 2004^121^ | Ineligible intervention
Smit, 2012^122^ | Ineligible outcome
Smith, 2010^123^ | Ineligible population
Sprangers, 2015^124^ | Ineligible study design
Stacpoole, 2015^125^ | Ineligible study design
Stancliffe, 1999^126^ | Ineligible date
Sutor, 2002^127^ | Ineligible publication type
Thomas, 2005^128^ | Ineligible population
Thomas, 2017^129^ | Ineligible intervention
Tjia, 2017^130^ | Ineligible study design
Torres-Castro, 2022^131^ | Ineligible study design
Totsika, 2008^132^ | Ineligible study design
Traynor, 2018^133^ | Ineligible intervention
Tseng, 2019^134^ | Ineligible country
Turner, 2009^135^ | Ineligible study design
Tyrer, 2017^136^ | Ineligible study design
van de Ven, 2012^137^ | Ineligible study design
van der Velde-van Buuringen, 2021^138^ | Ineligible intervention
van Duinen-van den, 2018^139^ | Ineligible population
van Weert, 2005^140^ | Ineligible study design
Veltro, 2006^141^ | Ineligible population
Verbeek, 2010^142^ | Ineligible study design
Verbeek, 2014^143^ | Ineligible intervention
Vink, 2013^144^ | Ineligible intervention
Volicer, 2006^145^ | Ineligible intervention
Wells, 2000^146^ | Ineligible date
Williams, 2011^147^ | Ineligible population
Williams, 2017^148^ | Ineligible outcome
Wouters, 2017^149^ | Ineligible intervention
Yang, 2021^150^ | Ineligible country
Yang, 2016^151^ | Ineligible country
Zijlmans, 2011^152^ | Ineligible population
Zijlmans, 2015^153^ | Ineligible population
Zoder-Martell, 2014^154^ | Ineligible population
Zwijsen, 2015^155^ | Ineligible outcome

1 Allen D, Tynan H. Responding to aggressive behavior: impact of training on staff members’ knowledge and confidence. Ment Retard. 2000;38(2):97–104.10804700
2 Almutairi H, Stafford A, Etherton-Beer C, . Association of Psychotropic Education with Quality of Life: A Before-After Study in Residential Aged Care Facilities. Drugs & Aging. 2022;39(12):949–958.36357654
3 Andersen C, Kolmos A, Andersen K, . Applying sensory modulation to mental health inpatient care to reduce seclusion and restraint: a case control study. Nordic Journal of Psychiatry. 2017;71(7):525–528.28719249
4 Anonymous. [Not Available]. Nursing Older People. 2002;14(7):8.
5 Appelhof B, Bakker C, van Duinen-van den IJCL, . Process Evaluation of an Intervention for the Management of Neuropsychiatric Symptoms in Young-Onset Dementia. Journal of the American Medical Directors Association. 2018;19(8):663–671.29653809
6 Arco L, du Toit E. Effects of adding on-the-job feedback to conventional analog staff training in a nursing home. Behavior Modification. 2006;30(5):713–35.16894238
7 Ayalon L, Bornfeld H, Gum AM, . The use of problem-solving therapy and restraint-free environment for the management of depression and agitation in long-term care. Clinical Gerontologist: The Journal of Aging and Mental Health. 2009;32(1):77–90.
8 Bakerjian D, Bettega K, Cachu AM, . The Impact of Music and Memory on Resident Level Outcomes in California Nursing Homes. Journal of the American Medical Directors Association. 2020;21(8):1045–1050.e2.32146039
9 Beck CK, Vogelpohl TS, Rasin JH, . Effects of behavioral interventions on disruptive behavior and affect in demented nursing home residents. Nursing Research. 2002;51(4):219–28.12131234
10 Bharani N, Snowden M. Evidence-based interventions for nursing home residents with dementia-related behavioral symptoms. Psychiatric Clinics of North America. 2005;28(4):985–1005, x.16325737
11 Bhat S, Rentala S, Nanjegowda RB, . Effectiveness of Milieu Therapy in reducing conflicts and containment rates among schizophrenia patients. Investigacion y educacion en enfermeria. 2020;38(1).
12 Bielderman A, Nieuwenhuis A, Hazelhof T, . Effects on staff outcomes and process evaluation of the educating nursing staff effectively (TENSE) program for managing challenging behavior in nursing home residents with dementia: A cluster-randomized controlled trial. International Journal of Nursing Studies. 2021;120:103982.34171518
13 Bird M, Llewellyn-Jones RH, Korten A. An evaluation of the effectiveness of a case-specific approach to challenging behaviour associated with dementia. Aging & Mental Health. 2009;13(1):73–83.19197692
14 Bjorkdahl A, Hansebo G, Palmstierna T. The influence of staff training on the violence prevention and management climate in psychiatric inpatient units. Journal of Psychiatric & Mental Health Nursing. 2013;20(5):396–404.22632809
15 Blair EW, Woolley S, Szarek BL, . Reduction of Seclusion and Restraint in an Inpatient Psychiatric Setting: A Pilot Study. Psychiatric Quarterly. 2017;88(1):1–7.26897657
16 Boettcher IF, Kemeny B, Boerman R. Training for and sustaining person-centered dementia care. Annals of Long-Term Care. 2004;12(12):26–28.
17 Borbasi S, Emmanuel E, Farrelly B, . A Nurse Practitioner initiated model of service delivery in caring for people with dementia. Contemporary Nurse. 2010;36(1–2):49–60.21254822
18 Bradshaw J, McGill P, Stretton R, . Implementation and Evaluation of Active Support. Journal of Applied Research in Intellectual Disabilities. 2004;17(3):139–148.
19 Buisson A, Ojardias E, Viceriat A, . [Interest of extrahospital multidisciplinary unit of neuro-psycho-geriatric intervened in nursing home: Analysis of 288 interventions]. Encephale. 2019;45(4):327–332.30879781
20 Burack OR, Weiner AS, Reinhardt JP. The impact of culture change on elders’ behavioral symptoms: a longitudinal study. Journal of the American Medical Directors Association. 2012;13(6):522–8.22464940
21 Burgio LD, Fisher SE, Fairchild J, . Quality of Care in the Nursing Home: Effects of Staff Assignment and Work Shift. The Gerontologist. 2004;44(3):368–377.15197291
22 Burgio LD, Stevens A, Burgio KL, . Teaching and maintaining behavior management skills in the nursing home. Gerontologist. 2002;42(4):487–496.12145376
23 Carbone E, Gardini S, Pastore M, . Cognitive Stimulation Therapy for Older Adults With Mild-to-Moderate Dementia in Italy: Effects on Cognitive Functioning, and on Emotional and Neuropsychiatric Symptoms. Journals of Gerontology Series B-Psychological Sciences & Social Sciences. 2021;76(9):1700–1710.33437991
24 Chao SY. A psychoeducational program for nursing staff managing problematic behaviors of elderly nursing home residents in Taiwan. Applied Nursing Research. 2005;18(4):205–12.16298696
25 Chen HM, Tsai LJ, Chao SY, . Study on the Effects of Individualized Learning Therapy on Cognitive Function and Behavioral and Psychological Symptoms of Dementia in the Institutionalized Older Adults. Journal of Nursing Research. 2016;24(4):300–310.
26 Chenoweth L, Jeon YH. Determining the efficacy of dementia care mapping as an outcome measure and a process for change: A pilot study. Aging and Mental Health. 2007;11(3):237–245.17558574
27 Chiappinotto S, Palese A, Longhini J. [Video calls between patients and relatives: a narrative review]. Assistenza Infermieristica e Ricerca:Air. 2022;41(3):120–128.36503950
28 Chou WY, Waszynski C, Kessler J, . Using positive images to manage resistance-to-care and combative behaviors in nursing home residents with dementia: A pilot study. Geriatric Nursing. 2016;37(3):215–20.27040950
29 Chou Y-C, Harman AD, Lin C-J, . Outcome Evaluation of Active Support Training in Taiwan. Research in Developmental Disabilities. 2011;32(3):1130–1136.21295439
30 Chrzescijanski D, Moyle W, Creedy D. Reducing dementia-related aggression through a staff education intervention. Dementia: The International Journal of Social Research and Practice. 2007;6(2):271–286.
31 Chung JCC. Activity Participation and Well-being of People with Dementia in Long-Term-Care Settings. OTJR Occupation, Participation and Health. 2004;24(1):22–31.
32 Çoban Arguvanli S, Karataş N, Başer M, . Effect of aggression management training program on knowledge and attitudes of nurses working at psychiatric clinics. Anadolu Psikiyatri Dergisi. 2015;16(5):323–328.
33 Cohen-Mansfield J, Jensen B. Do interventions bringing current self-care practices into greater correspondence with those performed premorbidly benefit the person with dementia? A pilot study. American Journal of Alzheimer’s Disease and other Dementias. 2006;21(5):312–317.
34 Cohen-Mansfield J, Marx MS, Dakheel-Ali M, . Can agitated behavior of nursing home residents with dementia be prevented with the use of standardized stimuli? Journal of the American Geriatrics Society. 2010;58(8):1459–64.20579167
35 Cohen-Mansfield J, Thein K, Marx MS. Predictors of the impact of nonpharmacologic interventions for agitation in nursing home residents with advanced dementia. Journal of Clinical Psychiatry. 2014;75(7):e666–71.25093482
36 Crotty M, Halbert J, Rowett D, . An outreach geriatric medication advisory service in residential aged care: a randomised controlled trial of case conferencing. Age & Ageing. 2004;33(6):612–7.15385274
37 da Silva Serelli L, Reis RC, Laks J, . Effects of the Staff Training for Assisted Living Residences protocol for caregivers of older adults with dementia: A pilot study in the Brazilian population. Geriatrics & gerontology international. 2017;17(3):449–455.26847046
38 Dechamps A, Alban R, Jen J, . Individualized Cognition-Action intervention to prevent behavioral disturbances and functional decline in institutionalized older adults: a randomized pilot trial. International Journal of Geriatric Psychiatry. 2010;25(8):850–60.19946868
39 DeYoung S, Just G, Harrison R. Decreasing aggressive, agitated, or disruptive behavior: perticipation in a behavior management unit. Journal of Gerontological Nursing. 2002;28(6):22–31.
40 DiBartolo MC, Vozzella SM, Rebert AN. The club concept: targeting behavioral issues in a residential setting for cognitively impaired adults. Journal of Gerontological Nursing. 2013;39(10):46–51.
41 Dichter MN, Quasdorf T, Schwab CG, . Dementia care mapping: effects on residents’ quality of life and challenging behavior in German nursing homes. A quasi-experimental trial. International Psychogeriatrics. 2015;27(11):1875–92.26138674
42 Dobbs D, Hobday J, Roker R, . Certified nursing assistants’ perspectives of the CARES R activities of daily living dementia care program. Applied Nursing Research. 2018;39:244–248.29422166
43 Duinen-van den Ijssel JC, Bakker C, Smalbrugge M, . Cost-consequence analysis of an intervention for the management of neuropsychiatric symptoms in young-onset dementia: Results from the BEYOND-II study. International Journal of Geriatric Psychiatry. 2020;35(1):131–137.31657080
44 Egan MY, Munroe S, Hubert C, . Caring for residents with dementia and aggressive behavior: impact of life history knowledge. Journal of Gerontological Nursing. 2007;33(2):24–30.17310660
45 Eggermont LH, Blankevoort CG, Scherder EJ. Walking and night-time restlessness in mild-to-moderate dementia: a randomized controlled trial. Age & Ageing. 2010;39(6):746–9.20823127
46 Eisch JS, Brozovic B, Colling K, . Nurse practitioner geropsychiatric consultation service to nursing homes. Geriatric Nursing. 2000;21(3):150–5.10864696
47 Engst C, Chhokar R, Robinson D, . Implementation of a scheduled toileting program in a long term care facility: evaluating the impact on injury risk to caregiving staff. AAOHN Journal. 2004;52(10):427–35.15508857
48 Fitzler S, Raia P, Buckley FO, Jr., . Does Nursing Facility Use of Habilitation Therapy Improve Performance on Quality Measures? American Journal of Alzheimer’s Disease & Other Dementias. 2016;31(8):687–692.
49 Fitzwater EL, Gates DM. Testing an intervention to reduce assaults on nursing assistants in nursing homes: a pilot study. Geriatric Nursing. 2002;23(1):18–23.11865253
50 Garland K, Beer E, Eppingstall B, . A comparison of two treatments of agitated behavior in nursing home residents with dementia: simulated family presence and preferred music. American Journal of Geriatric Psychiatry. 2007;15(6):514–21.
51 Gerdner LA. Use of individualized music by trained staff and family: translating research into practice. Journal of Gerontological Nursing. 2005;31(6):22–30; quiz 55-6.16138527
52 Gerolimatos LA, Page KS, Balestracci P, . Interdisciplinary development and implementation of a dementia skills training program in a VA community living center: a pilot study. Geriatric Nursing. 2018;39(4):400–406.29336830
53 Gillis K, Lahaye H, Dom S, . A person-centred team approach targeting agitated and aggressive behaviour amongst nursing home residents with dementia using the Senses Framework. International Journal of Older People Nursing. 2019;14(4):e12269.31469240
54 González-Fraile E, Ballesteros J, Rueda JR, . Remotely delivered information, training and support for informal caregivers of people with dementia. Cochrane Database of Systematic Reviews. 2021;2021(1).
55 Graske J, Schmidt A, Wolf-Ostermann K. More staff = better quality of life for people with dementia? results of a secondary data analysis in German shared-housing arrangements. Israel Journal of Health Policy Research. 2019;8(1):26.30786931
56 Hawranik P, Johnston P, Deatrich J. Therapeutic touch and agitation in individuals with Alzheimer’s disease. Western Journal of Nursing Research. 2008;30(4):417–34.18272750
57 Hazelhof TJ, Gerritsen DL, Schoonhoven L, . “The educating nursing staff effectively (TENSE) study”: design of a cluster randomized controlled trial. BMC Nursing. 2014;13(1):46.25606022
58 Henskens M, Nauta IM, van Eekeren MCA, . Effects of Physical Activity in Nursing Home Residents with Dementia: A Randomized Controlled Trial. Dementia & Geriatric Cognitive Disorders. 2018;46(1–2):60–80.30145595
59 Hicks-Moore SL. Relaxing music at mealtime in nursing homes: effects on agitated patients with dementia. Journal of Gerontological Nursing. 2005;31(12):26–32.
60 Hicks-Moore SL, Robinson BA. Favorite music and hand massage: Two interventions to decrease agitation in residents with dementia. Dementia: The International Journal of Social Research and Practice. 2008;7(1):95–108.
61 Holle D, Kruger C, Halek M, . Experiences of nursing staff using dementia-specific case conferences in nursing homes. American Journal of Alzheimer’s Disease & Other Dementias. 2015;30(3):228–37.
62 Holm A, Michel M, Stern GA, . The outcomes of an inpatient treatment program for geriatric patients with dementia and dysfunctional behaviors. Gerontologist. 1999;39(6):668–76.10650676
63 Hong GR. [Effects of multisensory stimulation using familiarity: persons with dementia in long-term care facility in Korea]. Journal of Korean Academy of Nursing. 2011;41(4):528–38.21964228
64 Hsu MH, Flowerdew R, Parker M, . Individual music therapy for managing neuropsychiatric symptoms for people with dementia and their carers: a cluster randomised controlled feasibility study. BMC Geriatrics. 2015;15:84.26183582
65 Husebo BS, Ballard C, Sandvik R, . Efficacy of treating pain to reduce behavioural disturbances in residents of nursing homes with dementia: cluster randomised clinical trial. BMJ. 2011;343:d4065.21765198
66 Husebo BS, Flo E, Aarsland D, . COSMOS--improving the quality of life in nursing home patients: protocol for an effectiveness-implementation cluster randomized clinical hybrid trial. Implementation Science. 2015;10:131.26374231
67 Irvine A, Beaty JA, Seeley JR, . Use of a dementia training designed for nurse aides to train other staff. Journal of Applied Gerontology. 2013;32(8):936–951.25364097
68 Isaac V, Kuot A, Hamiduzzaman M, . The outcomes of a person-centered, non-pharmacological intervention in reducing agitation in residents with dementia in Australian rural nursing homes. BMC Geriatrics. 2021;21(1):193.33743597
69 Jervis LL. Contending with “problem behaviors” in the nursing home. Archives of Psychiatric Nursing. 2002;16(1):32–8.11877604
70 Kerssens C, Sattler M, Monteiro A. Managing dementia symptoms and needs using technology. Journal of Gerontological Nursing. 2014;40(7):16–20.
71 Kim JS, Jung JS. [The effects of a folk play program on cognition, ADL, and problematic behavior in the elderly with dementia]. Daehan Ganho Haghoeji. 2005;35(6):1153–62.
72 Klapwijk MS, Caljouw MAA, Pieper MJC, . Change in quality of life after a multidisciplinary intervention for people with dementia: A cluster randomized controlled trial. International Journal of Geriatric Psychiatry. 2018;11:11.
73 Koczy P, Becker C, Rapp K, . Effectiveness of a multifactorial intervention to reduce physical restraints in nursing home residents. Journal of the American Geriatrics Society. 2011;59(2):333–339.21314651
74 Kolanowski A, Litaker M, Buettner L, . A randomized clinical trial of theory-based activities for the behavioral symptoms of dementia in nursing home residents. Journal of the American Geriatrics Society. 2011;59(6):1032–1041.21649633
75 Koskas P, Belqadi S, Mazouzi S, . [Behavioral and psychological symptoms of dementia in a pilot psychogeriatric unit: management and outcomes]. Revue Neurologique. 2011;167(3):254–9.20947112
76 Kovach CR, Taneli Y, Dohearty P, . Effect of the BACE intervention on agitation of people with dementia. Gerontologist. 2004;44(6):797–806.15611216
77 Kramarz E, Mok CLM, Westhead M, . Staff experience of team case formulation to address challenging behaviour on acute psychiatric wards: a mixed-methods study. Journal of Mental Health. 2022:1–12.
78 Kuiper D, Dijkstra GJ, Tuinstra J, . The influence of Dementia Care Mapping (DCM) on behavioural problems of persons with dementia and the job satisfaction of caregivers: A pilot study. Tijdschrift voor Gerontologie en Geriatrie. 2009;40(3):102–112.19731747
79 Landreville P, Dicaire L, Verreault R, . A training program for managing agitation of residents in long-term care facilities: description and preliminary findings. Journal of Gerontological Nursing. 2005;31(3):34–42; quiz 55-6.
80 Landreville P, Dicaire L, Verreault R, . Reducing agitation in elderly residents of long-term care facilities: Evaluation of a behavioral intervention program. Revue Francophone de Clinique Comportementale et Cognitive. 2011;16(1):p1.
81 Lamppu PJ, Finne-Soveri H, Kautiainen H, . Effects of Staff Training on Nursing Home Residents’ End-Of-Life Care: A Randomized Controlled Trial. Journal of the American Medical Directors Association. 2021;22(8):1699–1705.e1.34133971
82 Lay B, Blank C, Lengler S, . Preventing compulsory admission to psychiatric inpatient care using psycho-education and monitoring: feasibility and outcomes after 12 months. European Archives of Psychiatry & Clinical Neuroscience. 2015;265(3):209–17.25361537
83 Lay B, Drack T, Bleiker M, . Preventing compulsory admission to psychiatric inpatient care: Perceived coercion, empowerment, and self-reported mental health functioning after 12 months of preventive monitoring. Frontiers in Psychiatry. 2015;6(NOV).
84 Lichtenberg PA, Kemp-Havican J, MacNeill SE, . Pilot study of behavioral treatment in dementia care units. Gerontologist. 2005;45(3):406–410.15933281
85 Loi SM, Mazur A, Huppert D, . A pilot study using “apps” as a novel strategy for the management of challenging behaviors seen in people living in residential care. International Psychogeriatrics. 2017;29(4):637–643.27974056
86 Lykkeslet E, Gjengedal E, Skrondal T, . ‘On one’s own strength’ Healthcare providers’ experience with introducing Marte Meo Counselling in dementia care. International Journal of Older People Nursing. 2016;11(1):24–31.26220008
87 Maidment ID, Barton G, Campbell N, . MEDREV (pharmacy-health psychology intervention in people living with dementia with behaviour that challenges): the feasibility of measuring clinical outcomes and costs of the intervention. BMC Health Services Research. 2020;20(1):157.32122341
88 Manepalli J, Desai A, Sharma P. Psychosocial-environmental treatments for Alzheimer’s disease. Primary Psychiatry. 2009;16(6):39–47.
89 Massaia M, Villata E, Cappa G, . Behavioral disturbances in the Alzheimer’s care units: A six-months observation. Archives of Gerontology and Geriatrics. 2001;33(SUPPL.):245–252.
90 McAiney CA, Stolee P, Hillier LM, . Evaluation of the sustained implementation of a mental health learning initiative in long-term care. International Psychogeriatrics. 2007;19(5):842–858.17069667
91 McCreedy EM, Sisti A, Gutman R, . Pragmatic Trial of Personalized Music for Agitation and Antipsychotic Use in Nursing Home Residents With Dementia. Journal of the American Medical Directors Association. 2022;23(7):1171–1177.35038407
92 McGill P, Vanono L, Clover W, . Reducing challenging behaviour of adults with intellectual disabilities in supported accommodation: A cluster randomized controlled trial of setting-wide positive behaviour support. Research in Developmental Disabilities. 2018;81:143–154.29752027
93 Meehan T, Robertson S, Vermeer C. The impact of relocation on elderly patients with mental illness. Australian & New Zealand Journal of Mental Health Nursing. 2001;10(4):236–242.11703274
94 Mickus MA, Wagenaar DB, Averill M, . Developing effective bathing strategies for reducing problematic behavior for residents with dementia: The PRIDE approach. Journal of Mental Health and Aging. 2002;8(1):37–43.
95 Monette J, Champoux N, Monette M, . Effect of an interdisciplinary educational program on antipsychotic prescribing among nursing home residents with dementia. International Journal of Geriatric Psychiatry. 2008;23(6):574–579.17968860
96 Moniz-Cook E, Agar S, Silver M, . Can staff training reduce behavioural problems in residential care for the elderly mentally ill? International Journal of Geriatric Psychiatry. 1998;13(3):149–58.9565836
97 Morgan D, Stewart N, D’Arcy C, . Work stress and physical assault of nursing aides in rural nursing homes with and without dementia special care units. Journal of Psychiatric and Mental Health Nursing. 2005;12(3):347–358.15876243
98 Morley JE. Behavioral management in the person with dementia. Journal of Nutrition, Health and Aging. 2013;17(1):35–38.
99 Muniz R, Lopez-Alvarez J, Perea L, . CHROME Criteria and Quality of Life: A Pilot Study from Maria Wolff-Albertia. JAD Reports. 2021;5(1):613–624.34632299
100 O’Connell B, Guse L, Greenslade L. Does restructuring theory and clinical courses better prepare nursing students to manage residents with challenging behaviors in long-term care settings? Gerontology & Geriatrics Education. 2020;41(1):85–99.29381127
101 Oh H, Hur MH, Eom M. Development and analysis of the effects of caregiver training program on aggressive behavior in elders with cognitive impairment. Daehan Ganho Haghoeji. 2005;35(4):745–53.
102 Opie J, Doyle C, O’Connor DW. Challenging behaviours in nursing home residents with dementia: a randomized controlled trial of multidisciplinary interventions. International Journal of Geriatric Psychiatry. 2002;17(1):6–13.11802224
103 Orrell M, Hancock G, Hoe J, . A cluster randomised controlled trial to reduce the unmet needs of people with dementia living in residential care. International Journal of Geriatric Psychiatry. 2007;22(11):1127–1134.17394129
104 Park JS, Lee K. Modification of severe violent and aggressive behavior among psychiatric inpatients through the use of a short-term token economy. Journal of Korean Academy of Nursing. 2012;42(7):1062–9.23377602
105 Pouwels C, Spauwen P, van Heugten C, . Long-Term Effects of a Behavioural Management Technique for Nurses on Aggressive Behaviour in Brain-Injured Patients. Clinical Neuropsychiatry. 2019;16(2):107–115.34908944
106 Ray KD, Mittelman MS. Music therapy: A nonpharmacological approach to the care of agitation and depressive symptoms for nursing home residents with dementia. Dementia. 2017;16(6):689–710.26519453
107 Resnick B, Kolanowski A, Van Haitsma K, . Pilot Testing of the EIT-4-BPSD Intervention. American Journal of Alzheimer’s Disease & Other Dementias. 2016;31(7):570–579.
108 Robert P, Albrengues C, Fabre R, . Efficacy of serious exergames in improving neuropsychiatric symptoms in neurocognitive disorders: Results of the X-TORP cluster randomized trial. Alzheimer’s and Dementia: Translational Research and Clinical Interventions. 2021;7(1).
109 Rose J, Gallivan A, Wright D, . Staff training using positive behavioural support: The effects of a one-day training on the attributions and attitudes of care staff who work with people with an intellectual disability and challenging behaviour. International Journal of Developmental Disabilities. 2014;60(1):35–42.
110 Rosewarne R, Bruce A, McKenna M. Dementia programme effectiveness in long-term care. International Journal of Geriatric Psychiatry. 1997;12(2):173–82.9097210
111 Rota-Bartelink A. Supporting older people living with alcohol-related brain injury: the Wicking project outcomes. Care Management Journals. 2011;12(4):186–93.23214240
112 Roth DL, Stevens AB, Burgio LD, . Timed-event sequential analysis of agitation in nursing home residents during personal care interactions with nursing assistants. Journals of Gerontology - Series B Psychological Sciences and Social Sciences. 2002;57(5):P461–P468.12198105
113 Ryan NP, Scott L, McPhee M, . Evaluating the utility of a structured clinical protocol for reducing the impact of behavioural and psychological symptoms of dementia in progressive neurological diseases: A pilot study. Behavioural Neurology Vol 2018 2018, ArtID 5420531. 2018;2018.
114 Ryden MB, Snyder M, Gross CR, . Value-added outcomes: the use of advanced practice nurses in long-term care facilities. Gerontologist. 2000;40(6):654–62.11131082
115 Samus QM, Vavilikolanu A, Mayer L, . Cohort differences in dementia recognition and treatment indicators among assisted living residents in Maryland: did a change in the resident assessment tool make a difference? International Psychogeriatrics. 2013;25(12):2047–56.24059909
116 Sanchez A, Marante-Moar MP, Sarabia C, . Multisensory Stimulation as an Intervention Strategy for Elderly Patients With Severe Dementia: A Pilot Randomized Controlled Trial. American Journal of Alzheimer’s Disease & Other Dementias. 2016;31(4):341–50.
117 Sansone P, Schmitt L. Providing tender touch massage to elderly nursing home residents: a demonstration project. Geriatric Nursing. 2000;21(6):303–8.11135128
118 Shah A, De T. The effect of an educational intervention package about aggressive behaviour directed at the nursing staff on a continuing care psychogeriatric ward. International Journal of Geriatric Psychiatry. 1998;13(1):35–40.9489579
119 Sidani S, Streiner D, LeClerc C. Evaluating the effectiveness of the abilities-focused approach to morning care of people with dementia. International Journal of Older People Nursing. 2012;7(1):37–45.21631884
120 Simard J, Volicer L. Effects of Namaste Care on residents who do not benefit from usual activities. American Journal of Alzheimer’s Disease & Other Dementias. 2010;25(1):46–50.
121 Sloane PD, Hoeffer B, Mitchell C, . Effect of Person-Centered Showering and the Towel Bath on Bathing-Associated Aggression, Agitation, and Discomfort in Nursing Home Residents with Dementia: A Randomized, Controlled Trial. Journal of the American Geriatrics Society. 2004;52(11):1795–1804.15507054
122 Smit D, de Lange J, Willemse B, . The relationship between small-scale care and activity involvement of residents with dementia. International Psychogeriatrics. 2012;24(5):722–32.22221709
123 Smith RJ, Jennings JL, Cimino A. Forensic continuum of care with Assertive Community Treatment (ACT) for persons recovering from co-occurring disabilities: long-term outcomes. Psychiatric Rehabilitation Journal. 2010;33(3):207–18.20061257
124 Sprangers S, Dijkstra K, Romijn-Luijten A. Communication skills training in a nursing home: Effects of a brief intervention on residents and nursing aides. Clinical Interventions in Aging. 2015;10:311–319.25653513
125 Stacpoole M, Hockley J, Thompsell A, . The Namaste Care programme can reduce behavioural symptoms in care home residents with advanced dementia. International Journal of Geriatric Psychiatry. 2015;30(7):702–9.25338971
126 Stancliffe RJ, Hayden MF, Lakin KC. Effectiveness of challenging behavior IHP objectives in residential settings: a longitudinal study. Mental Retardation. 1999;37(6):482–93.10635669
127 Sutor B. Behavior problems in demented nursing home residents: a multifaceted approach to assessment and management. Comprehensive Therapy. 2002;28(4):183–8.12506487
128 Thomas C, Kitchen D, Smith A. The management of aggression care plans: Implementation and efficacy in a forensic learning disability service. The British Journal of Forensic Practice. 2005;7(2):3–9.
129 Thomas KS, Baier R, Kosar C, . Individualized Music Program is Associated with Improved Outcomes for U.S. Nursing Home Residents with Dementia. American Journal of Geriatric Psychiatry. 2017;25(9):931–938.
130 Tjia J, Hunnicutt JN, Herndon L, . Association of a Communication Training Program With Use of Antipsychotics in Nursing Homes. JAMA Internal Medicine. 2017;177(6):846–853.28418449
131 Torres-Castro S, Rabaneda-Bueno R, López-Ortega M, . Multicomponent Staff Training Intervention to Improve Residential Dementia Care (PROCUIDA-Demencia): A Mixed-Methods 2-Arm Cluster Randomized Controlled Pilot and Clinical Outcomes Study. Journal of the American Medical Directors Association. 2022;23(3):350–358.e5.34762845
132 Totsika V, Toogood S, Hastings RP, . Interactive training for active support: Perspectives from staff. Journal of Intellectual and Developmental Disability. 2008;33(3):225–238.18752095
133 Traynor V, Veerhuis N, Johnson K, . Evaluating the effects of a physical activity on agitation and wandering (PAAW) experienced by individuals living with a dementia in care homes. Journal of Research in Nursing. 2018;23(2–3):125–138.34394416
134 Tseng CF, Lee SH, Hsieh TC, . Smart Restored by Learning Exercise Alleviates the Deterioration of Cognitive Function in Older Adults with Dementia-A Quasi-Experimental Research. International Journal of Environmental Research & Public Health [Electronic Resource]. 2019;16(7):09.
135 Turner J, Snowdon J. An innovative approach to behavioral assessment and intervention in residential care: A service evaluation. Clinical Gerontologist: The Journal of Aging and Mental Health. 2009;32(3):260–275.
136 Tyrer P, Tarabi SA, Bassett P, . Nidotherapy compared with enhanced care programme approach training for adults with aggressive challenging behaviour and intellectual disability (NIDABID): cluster-randomised controlled trial. Journal of Intellectual Disability Research. 2017;61(6):521–531.28124397
137 van de Ven G, Draskovic I, Adang EM, . Improving person-centred care in nursing homes through dementia-care mapping: design of a cluster-randomised controlled trial. BMC Geriatrics. 2012;12:1.22214264
138 van der Velde-van Buuringen M, Achterberg WP, Caljouw MAA. Daily garden use and quality of life in persons with advanced dementia living in a nursing home: A feasibility study. Nursing Open. 2021;8(3):1243–1253.33348453
139 van Duinen-van den IJCL, Appelhof B, Zwijsen SA, . Behavior and Evolution of Young ONset Dementia part 2 (BEYOND-II) study: an intervention study aimed at improvement in the management of neuropsychiatric symptoms in institutionalized people with young onset dementia. International Psychogeriatrics. 2018;30(3):437–446.28595662
140 van Weert JC, van Dulmen AM, Spreeuwenberg PM, . Behavioral and mood effects of snoezelen integrated into 24-hour dementia care. Journal of the American Geriatrics Society. 2005;53(1):24–33.15667372
141 Veltro F, Falloon I, Venditteli N, . Effectiveness of cognitive-behavioural group therapy for inpatients. Clinical Practice and Epidemiology in Mental Health. 2006;2.
142 Verbeek H, Zwakhalen SM, van Rossum E, . Dementia care redesigned: Effects of small-scale living facilities on residents, their family caregivers, and staff. Journal of the American Medical Directors Association. 2010;11(9):662–70.21030001
143 Verbeek H, Zwakhalen SM, van Rossum E, . Effects of small-scale, home-like facilities in dementia care on residents’ behavior, and use of physical restraints and psychotropic drugs: a quasi-experimental study. International Psychogeriatrics. 2014;26(4):657–68.24411467
144 Vink A, Zuidersma M, Boersma F, . The effect of music therapy compared with general recreational activities in reducing agitation in people with dementia: A randomised controlled trial. International Journal of Geriatric Psychiatry. 2013;28(10):1031–1038.23280604
145 Volicer L, Simard J, Pupa JH, . Effects of Continuous Activity Programming on Behavioral Symptoms of Dementia. Journal of the American Medical Directors Association. 2006;7(7):426–431.16979086
146 Wells DL, Dawson P, Sidani S, . Effects of an abilities-focused program of morning care on residents who have dementia and on caregivers. Journal of the American Geriatrics Society. 2000;48(4):442–449.10798473
147 Williams DE, Grossett DL. Reduction of restraint of people with intellectual disabilities: an organizational behavior management (OBM) approach. Research in Developmental Disabilities. 2011;32(6):2336–9.21890318
148 Williams KN, Perkhounkova Y, Herman R, . A Communication Intervention to Reduce Resistiveness in Dementia Care: A Cluster Randomized Controlled Trial. Gerontologist. 2017;57(4):707–718.27048705
149 Wouters H, Scheper J, Koning H, . Discontinuing Inappropriate Medication Use in Nursing Home Residents: A Cluster Randomized Controlled Trial. Annals of Internal Medicine. 2017;167(9):609–617.29052691
150 Yang MH, Yang ST, Wang TF, . Effectiveness of a Sexuality Workshop for Nurse Aides in Long-Term Care Facilities. International Journal of Environmental Research & Public Health [Electronic Resource]. 2021;18(23):24.
151 Yang YP, Lee FP, Chao HC, . Comparing the Effects of Cognitive Stimulation, Reminiscence, and Aroma-Massage on Agitation and Depressive Mood in People With Dementia. Journal of the American Medical Directors Association. 2016;17(8):719–24.27168052
152 Zijlmans LJ, Embregts PJ, Gerits L, . Training emotional intelligence related to treatment skills of staff working with clients with intellectual disabilities and challenging behaviour. Journal of Intellectual Disability Research. 2011;55(2):219–30.21199045
153 Zijlmans LJ, Embregts PJ, Gerits L, . The effectiveness of staff training focused on increasing emotional intelligence and improving interaction between support staff and clients. Journal of Intellectual Disability Research. 2015;59(7):599–612.25171725
154 Zoder-Martell KA, Dufrene BA, Tingstrom DH, . Training direct care staff to increase positive interactions with individuals with developmental disabilities. Research in Developmental Disabilities. 2014;35(9):2180–2189.24915647
155 Zwijsen S, Gerritsen D, Eefsting J, . Coming to grips with challenging behaviour: A cluster randomised controlled trial on the effects of a new care programme for challenging behaviour on burnout, job satisfaction and job demands of care staff on dementia special care units. International Journal of Nursing Studies. 2015;52(1):68–74.25458804

## RISK OF BIAS ASSESSMENTS

### KQ1 RANDOMIZED CONTROLLED TRIALS (ROB-2)

### KQ3 RANDOMIZED CONTROLLED TRIALS (ROB-2)

### KQ2 NONRANDOMIZED COMPARISON STUDIES (ROBINS-I)

### KQ3 NONRANDOMIZED COMPARISON STUDIES (ROBINS-I)

## RESULTS FOR HEALTH CARE WORKER-FOCUSED INTERVENTION COMPONENTS ONLY

Study; N Clusters; N Patients; Primary outcome | Outcome; Direction; Follow-Up | Results
Health Care Teams-Only Interventions
Deudon, 2009^51^; 16 nursing homes; 306 patients randomized; Primary outcome: CAMI and observation scale | CMAI; Lower=better; 8 weeks; 20 weeks | Baseline; Staff training to manage behavioral and psychological symptoms of dementia: 53.08 (SD=18.1); Control: 48.21 (SD=15.9); 8 weeks; Staff training to manage behavioral and psychological symptoms of dementia: 45.48 (SD=13.9); Control: 45.59 (SD=13.9); 20 weeks; Staff training to manage behavioral and psychological symptoms of dementia: 47 (SD=16); Control: 47.54 (SD=18.1)
Testad, 2016^43^; 24 care homes; 274 patients randomized; Primary outcome: use of restraint | CMAI; Lower=better; 7 months | Baseline; Trust before restraint: 40.1 (SD=12.5); Control: 44.8 (SD=14.4); 7 month follow-up; trust before restraint: 37 (SD=11.6); Control: 41.2 (SD=14.3); P value 0.078
Livingston 2019^38^; 20 clusters; 404 patients randomized; Primary outcome: CMAI | CMAI; Lower=better; 8 months | Baseline; Managing agitation and raising quality of life: 42 (SD=16); Treatment as usual: 44 (SD=15); 8 months follow-up; Managing agitation and raising quality of life: 42 (SD=16); Treatment as usual: 44 (SD=17); Adjusted mean difference=−0.40 (95% CI [−3.89, 3.09]) (p value 0.8226)
Deudon, 2009^51^; 16 nursing homes; 306 patients randomized; Primary outcome: CAMI and observation scale | Observation Scale; Lower=better; 8 weeks; 20 weeks | Baseline; Staff training to manage behavioral and psychological symptoms of dementia: 22.22 (SD=31.9); Control: 13.26 (SD=20); 8 weeks; Staff training to manage behavioral and psychological symptoms of dementia: 11.73 (SD=21.6); Control: 10.89 (SD=19.8); 20 weeks; Staff training to manage behavioral and psychological symptoms of dementia: 7.58 (SD=14.7); Control: 9.91 (SD=15.8)
Fukuda, 2018^41^; 17 long term care or nursing facilities; 400 patients randomized; Primary outcome: NPI | NPI; Lower=better; 30 days | Baseline; Educational intervention mean: 27.5 (SD=22.6); Control mean: 25.5 (SD=27.3); 30-day follow-up; Educational intervention mean: 22.7 (SD=23.4); Control mean: 25.1 (SD=26.7)
Teri, 2005^56^; 4 assisted living residencies; 31 patients randomized; Primary outcome: NR | NPI; Lower=better; 8 weeks | Baseline; STAR mean: 12.6 (SD=13.4); Control mean: 6.7 (SD=10.6); 8 weeks; STAR mean: 9.1 (SD=9.3); Control mean: 9.4 (SD=13.2); Z score −2.15 (p value 0.031)
Testad, 2016^43^; 24 care homes; 274 patients randomized; Primary outcome: use of restraint | NPI; Lower=better; 7 months | Baseline; Trust before restraint mean: 12.1 (SD=12.3); Control mean: 18.2 (SD=17.5); 7 months; Trust before restraint mean: 17.7 (SD=19.9); Control mean: 19.8 (SD=19.4); (p value 0.207)
Livingston, 2019^38^; 20 clusters; 404 patients randomized; Primary outcome: CMAI | NPI; Lower=better; 8 months | Baseline; Managing agitation and raising quality of life: 14 (SD=14); Treatment as usual: 16 (SD=16); 8 months follow-up; Managing agitation and raising quality of life: 14 (SD=16); Treatment as usual: 16 (SD=14); Adjusted mean difference: −0.84 (95% CI [−5.51, 3.84]) (p value 0.726)
Leone, 2012^61^; 24 care homes; 274 patients randomized; Primary outcome: NR | NPI-ES- Affective; Lower=better; 4 weeks; 3 months | Baseline; Stimulation intervention group; Affective subgroup mean 3.56 (SD=4.93); Usual care; Affective subgroup mean 4.76 (SD=6.43); 4 weeks; Stimulation intervention group; Affective subgroup mean 5.84 (SD=6.32); Usual care; Affective subgroup mean 4.36 (SD=5.71); Mean difference: 2.52 (SD=6.08) (p value < 0.01); 3 months; Stimulation intervention; Affective subgroup mean 4.41 (SD=6.21); Usual care; Affective subgroup mean 4.70 (SD=5.70); Mean difference: 0.83 (SD=6.13) (p value < 0.01)
Leone, 2012^61^; 24 care homes; 274 patients randomized; Primary outcome: NR | NPI-ES- Apathy; Lower=better; 4 weeks; 3 months | Baseline; Stimulation intervention group; Affective subgroup mean 5.91 (SD=4.65); Usual care; Affective subgroup mean 5.18 (SD=4.64); 4 weeks; Stimulation intervention group; Affective subgroup mean 6.21 (SD=4.53); Usual care; Affective subgroup mean 4.72 (SD=4.29); Mean difference: 0.42 (SD=5.14) (p value > 0.05); 3 months; Stimulation intervention; Affective subgroup mean 5.94 (SD=4.63); Usual care; Affective subgroup mean 5.10 (SD=4.65); Mean difference: −0.05 (SD=5.83) (p value > 0.05)
Leone, 2012^61^; 24 care homes; 274 patients randomized; Primary outcome: NR | NPI-ES- Hyperactivity; Lower=better; 4 weeks; 3 months | Baseline; Stimulation intervention group; Affective subgroup mean 6.27 (SD=8.23); Usual care; Affective subgroup mean 5.89 (SD=8.45); 4 weeks; Stimulation intervention group; Affective subgroup mean 7.0 (SD=9.06); Usual care; Affective subgroup mean 6.15 (SD=8.12); Mean difference: 0.76 (SD=4.31) (p value p > 0.05); 3 months; Stimulation intervention; Affective subgroup mean 7.47 (SD=11.82); Usual care; Affective subgroup mean 6.69 (SD=8.33); Mean difference: 1.2 (SD=9.81) (p value > 0.05)
Leone, 2012^61^; 24 care homes; 274 patients randomized; Primary outcome: NR | NPI-ES- Psychotic; Lower=better; 4 weeks; 3 months | Baseline; Stimulation intervention group; Affective subgroup mean 2.15 (SD=4.48); Usual care; Affective subgroup mean 2.16 (SD=5.02); 4 weeks; Stimulation intervention group; Affective subgroup mean 3.12 (SD=5.96); Usual care; Affective subgroup mean 1.28 (SD=2.87); Mean difference: 0.99 (SD=5.65) (p value < 0.01); 3 months; Stimulation intervention; Affective subgroup mean 2.77 (SD=5.69); Usual care; Affective subgroup mean 2.18 (SD=4.30); Mean difference: 0.49 (SD=6.3) (p value < 0.01)
Deudon, 2009^51^; 16 nursing homes; 306 patients randomized; Primary outcome: CMAI and OS | NPI-hyperactivity; Lower=better; 8 weeks; 20 weeks | Baseline; Staff training to manage behavioral and psychological symptoms of dementia: 49.89 (SD=53.1); Control 35.68 (SD=40); 8 weeks; Staff training to manage behavioral and psychological symptoms of dementia: 43.62 (SD=51.2); Control 39.1 (SD=41.4); 20 weeks; Staff training to manage behavioral and psychological symptoms of dementia: 44.87 (SD=51.7); Control 42.2 (SD=55.9)
Deudon, 2009^51^; 16 nursing homes; 306 patients randomized; Primary outcome: CMAI and OS | NPI-psychosis; Lower=better; 8 weeks; 20 weeks | Baseline; Staff training to manage behavioral and psychological symptoms of dementia: 10.22 (SD=14.7); Control 6.14 (SD=10.6); 8 weeks; Staff training to manage behavioral and psychological symptoms of dementia: 8.46 (SD=13.3); Control 7.02 (SD=12.4); 20 weeks; Staff training to manage behavioral and psychological symptoms of dementia: 8.68 (SD=13.5); Control 6.5 (SD=11.4)
Testad, 2016^43^; 24 care homes; 274 patients randomized; Primary outcome: use of restraint | NPI-agitation scale; Lower=better; 7 months | Baseline; Trust before restraint mean: 4.6 (SD=6.4); Control mean: 5.3 (SD=7.2); 7 months; Trust before restraint mean: 5.5 (SD=8.6); Control mean: 6.6 (SD=8.5); P value 0.702
Teri 2005^56^; 4 assisted living residencies; 31 patients randomized; Primary outcome: NR | Agitated behavior in dementia; Lower=better; 8 weeks | Baseline; STAR 9.4 (SD=6.5); Control 9.4 (SD=9); 8 weeks; STAR 5.6 (SD=5.1); Control 9 (SD=9); Z score −6.75 (p value <0.001)
Deudon, 2009^51^; 16 nursing homes; 306 patients randomized; Primary outcome: CMAI and OS | Difference in overall score on sub-index; Uncertain; 8 weeks; 20 weeks | Baseline; Staff training to manage behavioral and psychological symptoms of dementia: 31.02 (SD=5.50); Control 31.29 (SD=9.3); 8-week follow-up; Staff training to manage behavioral and psychological symptoms of dementia 32.2 (SD=5.4); Control 32.61 (SD=10.1); 20-week follow-up; Staff training to manage behavioral and psychological symptoms of dementia: 31.78 (SD=7.2); Control 30.78 (SD=8.6)
Deudon, 2009^51^; 16 nursing homes; 306 patients randomized; Primary outcome: CMAI and observation scale | Psychotropic drugs; Lower=better; 8 weeks; 20 weeks | Baseline; Intervention: 2.52 (SD=1.3); Control: 2.68 (SD=1.65); 8-week follow-up; Intervention: 2.62 (SD=1.3); Control: 2.76 (SD=1.6); 20 week follow-up; Intervention: 2.51 (SD=1.3); Control: 2.81 (SD=1.6)
Testad 2016^43^; 24 care homes; 274 patients randomized; Primary outcome: use of restraint | Antipsychotics; Lower=better; 7 months | Baseline; Trust before restraint: 14.70%; Control: 35.90%; 7 month follow-up; Trust before restraint: 17.70%; Control 38.40%
Livingston, 2019^38^; 20 clusters; 404 patients randomized; Primary outcome: CMAI | Psychotropic medication; Lower=better; 8 months | Baseline; Managing agitation and raising quality of life: 75/189; Treatment as usual 107/215; 8 month follow-up; Managing agitation and raising quality of life: 66/155; Treatment as usual 78/163; Adjusted odds ratio: 1.20 (95% CI [0.61, 2.39]) (p value 0.597)
Livingston, 2019^38^; 20 clusters; 404 patients randomized; Primary outcome: CMAI | DEMQOL-Proxy; Higher=better; 8 months | Managing agitation and raising quality of life; vs treatment as usual adjusted mean difference: 0.09 (95% CI [−3.87, 4.05])

## RESULTS FOR HEALTH CARE TEAM AND PATIENT INTERVENTIONS

Study; N clusters; N patients; Primary outcome | Outcome; Direction; Follow-Up | Results
Health Care Team and Patient Interventions
Lichtwarck, 2018^42^; 33 nursing homes; 229 patients; Primary outcome: NPI | CMAI; Higher=better; 8 weeks; 12 weeks | Baseline; TIME intervention: 68.5 (95% CI [64.5, 72.5]); Usual care: 70.2 (95% CI [66.5, 74.0]); 8 weeks; TIME intervention: 61.5 (95% CI [57.4, 65.7]); Usual care: 68 (95% CI [64.3, 71.8]); Mean difference: 0.23 (p value 0.026); 12 weeks; TIME intervention: 59.4 (95% CI [55.2, 63.6]); Usual care: 67.1 (95% CI [63.3, 70.9]); Mean difference: 0.29 (p value 0.006)
Pieper, 2016^83^; 12 nursing homes; 288 patients randomized; Primary outcome: CMAI and NPI | CMAI; Lower=better; 3 months; 6 months | Baseline; STA OP! mean: 46 (SD=17.2); Usual care mean: 47.7 (SD=19); Overall adjusted mean difference between the intervention and control baseline to 6 months −3.45 (95% CI [−7.68, 0.78]) (p value 0.05)
Moniz-Cook, 2017^62^; 63 care homes; 832 patients randomized; Primary outcome: NPI | CMAI; Lower=better; 4 months; 7 months | Baseline; Staff e-learning mean: 54.61 (SD=20.43); Usual care mean: 53.3 (SD=16.49); Difference in change between baseline to 7-month follow-up between groups with clustering: 0.045
Chenoweth, 2009^84^; 15 care sites; 289 patients randomized; Primary outcome: CMAI | CMAI; Lower=better; 4 months; 8 months | Baseline; Person-centered care mean: 47.5 (SD=9.1); Dementia-care mapping mean: 46.1 (SD=6.5); UC mean: 50.3 (SD=6.8); 4-month follow-up; Person-centered care mean: 41.7 (SD=9.2); dementia-care mapping mean: 45.1 (SD=6.6); UC mean: 58.7 (SD=6.9); 8-month follow-up; Person-centered care mean: 37.2 (SD=9.1); Dementia-care mapping mean: 43.7 (SD=6.5); UC mean: 57.7 (SD=6.8); Person-centered care vs UC mean difference: 13.6 (95% CI [3.3, 23.9]) (p value 0.01); Dementia-care mapping vs UC mean difference: 10.9 (95% CI [0.7, 21.1]) (p value 0.04); Arm x time p value: 0.005
van de Ven, 2013^48^; 14 care homes; 268 patients randomized; Primary outcome: CMAI | CMAI; Lower=better; 4 months; 8 months | Baseline; Dementia care mapping mean:; 46.61 (SE=1.91); Usual care mean: 45.29 (SE=1.56); 4 months; Dementia care mapping: 47.86 (SE=1.88); Usual care mean: 44.32 (SE=1.63); 8 months; Dementia care mapping: 48.18 (SE=2.3); Usual care mean: 45.81 (SE=1.97); Mean difference: 2.4 (95% CI [−2.7, 7.6)] (p value 0.34); Interaction between group and time: p value 0.473
Chenoweth, 2014^82^; 38 clusters; 601 patients randomized; Primary outcome: NR | CMAI; Lower=better; 6 months; 8 months | Baseline; Person-centered care mean: 64 (95% CI [56, 72]); Usual care and usual environment: 52 (95% CI [43, 61]); 6 months follow-up; Person-centered care mean: 58 (95% CI [49, 67]); Usual care and usual environment mean: 53 (95% CI [43, 63]); 8 months follow-up; Person-centered care mean: 46 (95% CI [37, 56]); Usual care and usual environment: 51 (95% CI [41, 62]); Person-centered care vs usual care and usual environment p value: 0.06
Ballard, 2018^40^; 69 clusters; 832 patients randomized; Primary outcome: QOL | CMAI; Lower=better; 9 months | WHELD (staff training in person-centered care) mean: −4.13; Continuous mean: 0.14; Mean difference (in longitudinal change):; −4.27 (SE=1.59) (95% CI [−7.39, −1.15])
Ballard, 2016^81^; 16 nursing homes; 277 patients randomized; Primary outcome: CMAI | CMAI; Lower=better; 9 months | Baseline; Antipsychotic review mean: 46.54 (SD=15.97); No antipsychotic review; Baseline mean:47.06 (SD=15.87); 9-month follow-up; Antipsychotic review mean: 49.1 (SD=20.14); No antipsychotic review mean: 46.16 (SD=18.17); Antipsychotic review vs no antipsychotic review: 4.6 (95% CI [−1.43, 10.63]); Baseline; Social interaction mean: 47.91 (SD=16.74); No Social interaction mean: 45.57 (SD=14.92); 9-month follow-up:; Social interaction mean: 50.75 (SD=21.77); No social interaction mean: 44.6 (SD=15.72); Social interaction vs no social interaction:; 4.96 (95% CI −1.33, 11.25)
Rapp, 2013^49^; 18 nursing homes; 304 patients randomized; Primary outcome: CMAI | CMAI; Lower=better; 10 months | Training and activity therapy mean: 52.94 (SD=22.97); Treatment as usual mean: 53.86 (SD=16.64); 10 months; Training and activity therapy mean: 46.24 (SD=16.27); Treatment as usual mean: 56.38 (SD=17.23); Mean difference: 6.24 (95% CI [2.03, 14.14]) p value (0.009)
Fossey, 2006^55^; 12 nursing homes; 346 patients randomized; Primary outcome: neuroleptic use | CMAI; Lower=better; 12 months | Baseline; Training and staff support mean: 41.6 (SD=7.2); Usual care mean: 42 (SD=5.6); 12-month follow-up; Training and staff support vs usual care weighted mean difference: 0.3 (95% CI [−8.3, 8.9])
Zwijsen, 2014^45^; 17 dementia special care units; 659 patients randomized; Primary outcome: CMAI | CMAI; Lower=better; 20 months | Grip on Challenging Behavior mean; T1 (4 months): 47 (SD=18); T2 (8 months): 52 (SD=19); T3 (12 months): 51 (SD=18); T4 (16 months): 50 (SD=17); T5 (20 months): 51 (SD=19); Usual care mean; T0 (Baseline): 51 (SD=18); T1 (4 months): 55 (SD=19); T2 (8 months): 53 (SD=20); T3 (12 months): 53 (SD=20); T4 (16 months): 56 (SD=22)
Chapman, 2007^53^; 2 nursing homes; 118 patients randomized; Primary outcome: NR | CMAI-aggressive behavior subscale; Lower=better; 8 weeks | Baseline; AICT mean: 1.18 (SD=0.47); Usual care: 1.23 (SD=0.48); 8 weeks; AICT mean: 1.10 (SD=0.25); Usual care: 1.16 (SD=0.39); F statistic 0.06
Chapman, 2007^53^; 2 nursing homes; 118 patients randomized; Primary outcome: NR | CMAI-physically nonaggressive behavior; Lower=better; 8 weeks | Baseline; AICT mean: 1.64 (SD=1.10); Usual care: 1.36 (SD=0.52); 8 weeks; AICT mean: 1.30 (SD=0.60); Usual care: 1.29 (SD=0.49); F statistic: 4.22 (p value ≤ 0.05)
Chapman, 2007^53^; 2 nursing homes; 118 patients randomized; Primary outcome: NR | CMAI- verbally agitated behavior; Lower=better; 8 weeks | Baseline; AICT mean: 1.44 (SD=0.48); Usual care: 1.44 (SD=0.61); 8 weeks; AICT mean: 1.28 (SD=0.42); Usual care: 1.36 (SD=0.53); F statistic: 1.43
Moniz-Cook, 2017^62^; 63 care homes; 832 patients randomized; Primary outcome: NPI | CMAI-physical/ aggressive; Lower=better; 4 months; 7 months | Baseline; Staff e-learning mean: 17.2 (SD=9.47); Usual care mean: 16.94 (SD=7.79); 7 month mean difference 0.39 (95% CI [−1.77, 2.55])
Moniz-Cook, 2017^62^; 63 care homes; 832 patients randomized; Primary outcome: NPI | CMAI-physical/ nonaggressive; Lower=better; 4 months; 7 months | Baseline; Staff e-learning mean: 19.55 (SD=8.93); Usual care mean: 19.29 (SD=8.62); 7 month mean difference: 0.46 (95% CI [−1.66, 2.58])
Moniz-Cook, 2017^62^; 63 care homes; 832 patients randomized; Primary outcome: NPI | CMAI-verbal/ aggressive; Lower=better; 4 months; 7 months | Baseline; Staff e-learning mean: 5.68 (SD=3.21); Usual care mean: 5.49 (SD=3.14); 7 month mean difference: 0.60 (95% CI [−0.16, 1.36])
Moniz-Cook, 2017^62^; 63 care homes; 832 patients randomized; Primary outcome: NPI | CMAI-verbal/ nonaggressive; Lower=better; 4 months; 7 months | Baseline; Staff e-learning mean: 12.13 (SD=6.4); Usual care mean: 11.58 (SD=5.68); 7 month mean difference: 0.63 (95% CI [−1.17, 2.43])
Appelhof, 2019^39^; 13 special care units; 274 patients randomized; Primary outcome: CMAI | CMAI-aggressive; Lower=better; 9 months | Grip on neuropsychiatric symptoms vs usual care regression coefficient: 0.495 (95% CI [−0.448, 1.438]) (p value 0.303)
Appelhof, 2019^39^; 13 special care units; 274 patients randomized; Primary outcome: CMAI | CMAI-verbal; Lower=better; 9 months | Regression coefficient: −0.176; (95% CI [−1.065, 0.713]) (p value 0.697)
Rokstad, 2013^60^; 15 nursing homes; 624 patients randomized; Primary outcome: BARS | CMAI-agitation; Lower=better; 11 months | Baseline; DCM mean 18.8 (SD=9.2); VPM mean 19.7 (SD=9.8); Control 17.6 (SD=8.4); 11- month follow-up; DCM: 17.2 (SD=9); VPM: 18.5 (SD=8.6); Control: 17.8 (SD=8); DCM vs control regression coefficient: −2 (95% CI [−5.1, 1.1]) (p value 0.19); VPM vs control regression coefficient: 1.1 (95% CI [−3.8; 1.6]) (p value 0.42)
Lichtwarck, 2018^42^; 33 nursing homes; 229 patients; Primary outcome: NPI | NPI; Lower=better; 8 weeks; 12 weeks | Baseline; TIME mean: 44.2 (95% CI [39.9, 48.0]); Brief education-only intervention mean: 49.0 (95% CI [45.0, 53.0]); 8 weeks; TIME mean: 33.7 (95% CI, 29.3, 38.2); Brief education-only intervention: 41.3 (95% CI [37.3, 45.4]); Standard mean difference: 0.12 (p value 0.317); 12 weeks; TIME mean: 31.1 (95% CI [26.7, 35.6]); Brief education-only intervention: 41.4 (95% CI [37.3, 45.5]); Standard mean difference: 0.25 (p value 0.053)
Stensvik, 2022^34^; 17 nursing home; 309 patients randomized; Primary outcome: neuropsychiatric symptoms | NPI-Q 12 item scale; Lower=better; 3 months | Baseline; Modified comprehensive geriatric assessment and case conferences mean: 4.5 (SD=5.2); Usual care mean: 4.9 (SD=5.4); 3 months; Modified comprehensive geriatric assessment and case conferences mean: 3.9 (SD=3.7); Usual care mean: 5.4 (SD=6); Difference −1 (95% CI [−2.4, 0.5]) (p value 0.19)
Pieper, 2016^106^; 12 nursing homes; 288 patients randomized; Primary outcome: CMAI and NPI | NPI-NH; Lower=better; 3 months; 6 months | Baseline; STA OP! mean: 17 (SD=16.4); Usual care mean: 14.3 (SD=12.9); Overall adjusted mean difference: −5.70 (95% CI [−8.88, −2.52]) (p value < 0.001)
Moniz-Cook, 2017^62^; 63 care homes; 832 patients randomized; Primary outcome: NPI | NPI; Lower= better; 4 months; 7 months | Baseline; Staff e-learning mean: 20.06 (SD=15.66); Usual care mean: 22.28 (SD=16.22); 7- month follow-up mean difference in score: 0.18 (95% CI [−3.68, 4.04])
Chenoweth, 2009^84^; 15 care sites; 289 patients randomized; Primary outcome: CMAI | NPI; Lower=better; 4 months; 8 months | Baseline; Person-centered care mean: 21.3 (SD=9.8); Dementia-care mapping mean: 12.7 (SD=5.1); UC mean: 16.9 (SD=5.3); 4-month follow-up; Person-centered care mean: 14.5 (SD=6.9); Dementia-care mapping mean: 16.8 (SD=5.1); UC mean: 20.2 (SD=5.4); 8-month follow-up; Person-centered care mean: 12.6 (SD=6.9); Dementia-care mapping mean: 13.5 (SD=5.1); UC mean: 15.3 (SD=5.3); Arm x time p value: 0.30
van de Ven, 2013^48^; 14 care homes; 268 patients randomized; Primary outcome: CMAI | NPI- NH; Lower=better; 4 months; 8 months | Baseline; Dementia care mapping: 5.35 (SD=0.94); Usual care: 6.28 (SD=0.88); 4 months; Dementia care mapping: 7.19 (SD=0.95); Usual care: 4.45 (SD=0.88); 8 months; Dementia care mapping: 6.28 (SD=0.92); Usual care: 4.45 (SD=0.88); Arm x time interaction P value = 0.022
Ballard, 2016^81^; 16 nursing homes; 277 patients randomized; Primary outcome: CMAI | NPI; Lower=better; 9 months | Baseline; Antipsychotic review mean: 12.52 (SD=13.89); No antipsychotic review; Baseline mean: 15.93 (SD=15.96); 9-month follow-up; Antipsychotic review mean: 14.62 (SD=13.36); No antipsychotic review mean: 13.05 (SD=11.13); Antipsychotic review vs no antipsychotic review: 7.37 (95% CI [1.53, 13.22]) (p value 0.02); Baseline; Social interaction mean: 15.05 (SD=15.51); No social interaction mean: 12.99 (SD=14.25); 9-month follow-up:; Social interaction mean: 14.89 (SD=12.35); No social interaction mean: 12.86 (SD=12.43); Social interaction vs no social interaction: 5.45 (95% CI [0.12, 10.77]) (p value <0.05)
Rokstad, 2013^60^; 15 nursing homes; 624 patients randomized; Primary outcome: BARS | NPI-Q; Lower=better; 11 months | Baseline; DCM mean: 5.2 (SD=4.7); VPM mean: 6.9 (SD5.1); Control mean: 4.1 (SD=3.9); 11 months; DCM mean: 5.3 (SD=5.5); VPM mean: 6.2 (SD=5.6); Control mean: 5.5 (SD=4.5); DCM vs control adj. regression coefficient: −2.7 (95%CI [−4.6, −0.7]) (p value 0.01); VPM vs control adj. regression coefficient: −2.4 (95% CI [−4.1, −0.6]) (p value 0.01)
Zwijsen, 2014^45^; 17 dementia special care units; 659 patients randomized; Primary outcome: CMAI | NPI-NH; Lower=better; 20 months | Grip on Challenging Behavior mean:; T1 (4 months): 1.9 (SD=2.2); T2 (8 months): 2.4 (SD=2.2); T3 (12 months): 2.4 (SD=2.3); T4 (16 months): 2.4 (SD=2.3); T5 (20 months): 2.4 (SD=2.4); Usual care mean:; T0 (Baseline): 2.7 (SD=2.2); T1 (4 months): 3.0 (SD=2.5); T2 (8 months): 3.0 (SD=2.5); T3 (12 months): 2.3 (SD=2.3); T4 (16 months): 3.3 (SD=2.8)
Lichtwarck, 201^42^; 33 nursing homes; 229 patients; Primary outcome: NPI | NPI-agitation/aggression; Lower=better; 8 weeks; 12 weeks | Baseline; TIME mean: 8.7 (95% CI [8.1, 9.4]); Brief education-only intervention mean: 8.4 (95% CI [7.8, 9.0]); 8 weeks; TIME mean: 6.1 (95% CI [5.4, 6.8]); Brief education-only intervention mean: 6.8 (95% CI [6.2, 7.5]); Standardized mean difference: 0.32 (p value 0.031); 12 weeks; TIME mean: 5.7 (95% CI [4.9, 6.4]); Brief education-only intervention mean: 7 (95% CI [6.3, 7.6]); Standardized mean difference: 0.47 (p value 0.002)
Stensvik, 2022^34^; 17 nursing home; 309 patients randomized; Primary outcome: neuropsychiatric symptoms | NPI-affective subscale; Lower=better; 3 months | Baseline; Modified comprehensive geriatric assessment and case conferences mean: 0.7 (SD=1.1); Usual care mean: 1 (SD=1.4); 3 months; Modified comprehensive geriatric assessment and case conferences mean: 0.6 (SD=1); Usual care mean: 0.8 (SD=1.4); Difference: 0.05 (95% CI [0.67, −0.2]) (p value 0.67)
Stensvik, 2022^34^; 17 nursing home; 309 patients randomized; Primary outcome: neuropsychiatric symptoms | NPI-agitation subscale; Lower=better; 3 months | Baseline; Modified comprehensive geriatric assessment and case conferences mean: 1.4 (SD=1.9); Usual care mean: 1.7 (SD=2.1); 3 months; Modified comprehensive geriatric assessment and case conferences mean: 1.5 (SD=2); Usual care mean: 2 (SD=2.5); Difference: −0.2 (95% CI [0.54, −0.8)] (p value 0.54)
Stensvik, 2022^34^; 17 nursing home; 309 patients randomized; Primary outcome: neuropsychiatric symptoms | NPI-apathy; Lower=better; 3 months | Baseline; Modified comprehensive geriatric assessment and case conferences mean: 0.7 (SD=1.1); Comparator mean: 0.6 (SD=1.1); 3 months; Modified comprehensive geriatric assessment and case conferences mean: 0.5 (SD=0.8); Comparator mean: 0.9 (SD=1.3); Difference: −0.5 (95% CI [−0.9, −0.05]) (p value 0.03)
Stensvik, 2022^34^; 17 nursing home; 309 patients randomized; Primary outcome: neuropsychiatric symptoms | NPI-psychosis; Lower=better; 3 months | Baseline; Modified comprehensive geriatric assessment and case conferences mean: 0.8 (SD=1.2); Usual care mean: 0.8 (SD=1.2); 3 months; Modified comprehensive geriatric assessment and case conferences mean: 0.8 (SD=1.2); Usual care mean: 0.9 (SD=1.3); Difference −0.25 (95% CI [−0.5, 0.1]) (p value 0.11)
Appelhof, 2019^39^; 13 special care units; 274 patients randomized; Primary outcome: CMAI | NPI-subscale for agitation/aggression.; Lower=better; 6 months | Grip on neuropsychiatric symptoms vs usual care Regression coefficient:; −0.001 (95% CI [−0.09, 0.087]) (p value 0.975)
Moniz-Cook, 2017^62^; 63 care homes; 832 patients randomized; Primary outcome: NPI | NPI-distress; Lower=better; 4 months; 7 months | Baseline; Staff e-learning mean: 4.77 (SD=6.63); Usual care mean: 4.82 (SD=6.5); Mean difference in score: 0.12 (95% CI [−1.64, 1.88])
Moniz-Cook, 2017^62^; 63 care homes; 832 patients randomized; Primary outcome: NPI | NPI-frequency; Lower=better; 4 months; 7 months | Baseline; Staff e-learning mean: 12.12 (SD=7.1); Usual care mean: 12.66 (SD=7.5); 7 months; Staff e-learning mean: 11.65 (SD=6.92); Usual care mean: 11.65 (SD=6.43); Difference in mean: 0.6 (95% CI [−1.18, 2.38])
Moniz-Cook, 2017^62^; 63 care homes; 832 patients randomized; Primary outcome: NPI | NPI-incidence; Lower=better; 4 months; 7 months | Baseline; Staff e-learning mean: 4.86 (SD=2.4); Usual care mean: 4.8 (SD=2.34)
Moniz-Cook, 2017^62^; 63 care homes; 832 patients randomized; Primary outcome: NPI | NPI-Severity; Lower=better; 7 months | Baseline; Staff e-learning mean: 7.55 (SD=4.8); Usual care mean: 7.97 (SD=4.87); 7 months; Staff e-learning mean: 7.29 (SD=4.44); Usual care mean: 7.25 (SD=4.45); Difference in mean: 0.45 (95% CI [−1.03, 1.93])
van de Ven, 2013^48^; 14 care homes; 268 patients randomized; Primary outcome: CMAI | NPI-agitation subscale; Lower=better; 4 months; 8 months | Baseline; Dementia care mapping mean: 0.63 (SD=0.17); Usual care mean: 0.77 (SD=0.16); 4 months; Dementia care mapping mean: 0.62 (SD=0.17); Usual care mean: 0.49 (SD=0.16); 8 months; Dementia care mapping mean: 0.52 (SD=0.17); Usual care mean: 0.6 (SD=0.16); P value: 0.862
Zwijsen, 2014^45^; 17 dementia special care units; 659 patients randomized; Primary outcome: CMAI | NPI - subscale for agitation; Lower=better; 20 months | OR 0.82 (95% CI 0.48, 1.39) (p value 0.47)
Kovach, 2006^58^; 14 long-term care facilities; 127 patients randomized; Primary outcome: NR | BEHAVE-Alzheimer’s Disease (AD) scale- o used to assess less subtle behavioral symptoms of discomfort, such as aggression and wandering; Lower=better; 2 weeks; 4 weeks | Baseline; STI: 7.43 (SD=6.75); Control: 6.80 (SD=5.47); 2 weeks; STI: 5.56 (SD=5.64); Control: 6.15 (SD=5.55); 4 weeks; STI: 4.68 (SD=4.06); Control: 4.96 (SD=4.39); F statistic: 0.70 (p value 0.5)
Moniz-Cook, 2017^62^; 63 care homes; 832 patients randomized; Primary outcome: NPI | Challenging Behavior Scale difficulty; Lower=better; 4 months; 7 months | Baseline; Staff e-learning mean: 11.22 (SD=10.37); Usual care mean: 11.03 (SD=10.59)
Moniz-Cook, 2017^62^; 63 care homes; 832 patients randomized; Primary outcome: NPI | Challenging Behavior Scale frequency; Lower=better; 4 months; 7 months | Baseline; Staff e-learning mean:21.42 (SD=14.59); Usual care mean: 21.38 (SD=14.87); Mean difference in score: 0.69 (95% CI [−1.67, 3.05])
Moniz-Cook, 2017^62^; 63 care homes; 832 patients randomized; Primary outcome: NPI | Challenging Behavior Scale (frequency × difficulty); Lower=better; 4 months; 7 months | Baseline; Staff e-learning mean: 34.99 (SD=35.16); Usual care mean: 34.64 (SD=35.65); Mean difference in score: −0.19 (95% CI [−6.69, 6.31])
Moniz-Cook, 2017^62^; 63 care homes; 832 patients randomized; Primary outcome: NPI | Challenging Behavior Scale incidence; Lower=better; 4 months; 7 months | Baseline; Staff e-learning mean: 7.07 (SD=4.04); Usual care mean: 6.93 (SD=4.55); Chi square 0.116
Kirkham, 2020^37^; 10 long term care facilities; Primary outcome: Antipsychotic use | Behavioral symptoms; Lower=better; 12 months | OPAL: 14.9 (SD=1.6); Self at baseline prior to intervention: 14.3 (SD=1.4); 12 months; OR: 0.96 (95% CI 0.8, 1.14) (p value 0.6)
Appelhof, 2019^39^; 13 special care units; 274 patients randomized; Primary outcome: CMAI | Antipsychotic use; Lower=better; 6 months | Grip on neuropsychiatric symptoms vs usual care; Regression coefficient: −0.002 (95% CI [−0.064, 0.06]) (p value 0.956)
Pieper, 2016^83^; 12 nursing homes; 288 patients randomized; Primary outcome: CMAI and NPI | Antipsychotic use; Lower=better; 3 months; 6 months | STA OP!: 51/ 144; Usual care: 51/ 138; OR 0.87 (95% CI 0.33, 2.30) (p value 0.78)
Moniz-Cook, 2017^62^; 63 care homes; 832 patients randomized; Primary outcome: NPI | Antipsychotic use; Lower=better; 7 months | Baseline; Staff e-learning: 30/202; Usual care:36/226; 7 month follow-up; Staff e-learning: 34/202; Usual care: 39/ 226; Chi-square >0.999
Chenoweth, 2009^84^; 15 care sites; 289 patients randomized; Primary outcome: CMAI | Antipsychotic use; Lower=better; 4 months; 8 months | Baseline; Person-centered care: 0.42%; Dementia-care mapping: 0.15%; Usual care: 0.19%; 4 months; Person-centered care: 0.30%; Dementia-care mapping: 0.19%; Usual care: 0.14%; 8 months; Person-centered care: 0.34%; Dementia-care mapping: 0.15%; UC: 0.14%; Baseline to 8 month x person-centered care and dementia-care mapping vs usual care interaction p value: 0.66
Ballard, 2018^40^; 69 clusters; 832 patients randomized; Primary outcome: QOL | Antipsychotic use; Lower=better; 9 months | Change in use from baseline WHELD (staff training in person-centered care): −0.1%; Change in use from baseline treatment as usual: −0.2%; Relative risk at 9 months: 1.06 (95% CI [0.62 1.82]) p value 0.82
Ballard, 2016^81^; 16 nursing homes; 277 patients randomized; Primary outcome: CMAI | Antipsychotic use; Lower=better; 9 months | Antipsychotic review vs no antipsychotic review; OR 0.17 (95% CI [0.05, 0.59]) (p value 0.006); Social interaction vs no social interaction; OR O.6 (95% CI [0.19, 1.91]) (p value 0.4)
Kirkham, 2020^37^; 10 long term care facilities; Primary outcome: Antipsychotic use | Antipsychotic use; Lower=better; 12 months | Baseline weighted mean: 28.6 (SD=1.3); OPAL 12-month follow-up weighted mean: 24.0 (SD=1.5); OR 0.73 (95% CI [0.58, 0.94]) (p value 0.01)
Zwijsen, 2014^45^; 17 dementia special care units; 659 patients randomized; Primary outcome: CMAI | Antipsychotic use; Lower=better; 20 months | Intervention; T1 (4 months): 23.3%; T2 (8 months): 25.9%; T3 (12 months): 24.3%; T4 (16 months): 23.0%; T5 (20 months): 22.6%; Control; T0 (Baseline): 27.9%; T1 (4 months): 28.1%; T2 (8 months): 27.4%; T3 (12 months): 26.0%; T4 (16 months): 20.0%
Appelhof, 2019^39^; 13 special care units; 274 patients randomized; Primary outcome: CMAI | PDU Anxiolytics; Lower=better; 6 months | Grip on neuropsychiatric symptoms vs usual care regression coefficient:; −0.033 (95% CI [−0.095, 0.029]) (p value 0.301)
Appelhof, 2019^39^; 13 special care units; 274 patients randomized; Primary outcome: CMAI | PDU Any psychotropic medication; Lower=better; 6 months | Regression coefficient: −0.023 (95% CI [−0.09, 0.044]) (p value 0.505)
Fossey, 2006^55^; 12 nursing homes; 346 patients randomized; Primary outcome: neuroleptic use | Neuroleptics; Lower=better; 12 months | Training and staff support vs Usual care weighted mean difference: 19.10% (95% CI [0.50%, 37.70%]) (p value 0.045)
Fossey, 2006^55^; 12 nursing homes; 346 patients randomized; Primary outcome: neuroleptic use | Psychotropics; Lower=better; 12 months | Training and staff support vs Usual care weighted mean difference: −5.9 (95% CI [−27.2, 15.5]) (p value 0.56)
Rapp, 2013^49^; 18 nursing homes; 304 patients randomized; Primary outcome: CMAI | Neuroleptics; Lower=better; 12 months | Baseline; Training and activity therapy: 0.263 (SD=0.052); Treatment as usual: 0.264 (SD=0.091); 12 months; Training and activity therapy: 0.23 (SD=0.06); Treatment as usual: 0.26 (SD=0.05); Adjusted mean difference: 0.03 (95% CI [0.01, 0.05]) (p value 0.04)
Rapp, 2013^49^; 18 nursing homes; 304 patients randomized; Primary outcome: CMAI | Cholinesterase inhibitors; Lower=better; 12 months | Baseline; Training and activity therapy: 0.084 (SD=0.022); Treatment as usual : 0.086 (SD=0.024); 12 months; Training and activity therapy : 0.19 (SD=0.06); Treatment as usual : 0.08 (SD=0.05); Adjusted mean difference: 0.09 (95% CI [0.05, 0.11]) (p value 0.01)
Zwijsen, 2014^45^; 17 dementia special care units; 659 patients randomized; Primary outcome: CMAI | Anxiolytics; Lower=better; 20 months | Grip on Challenging Behavior:; T1 (4 months): 21.7%; T2 (8 months): 17.3%; T3 (12 months): 17.6%; T4 (16 months): 18.4%; T5 (20 months): 21.2%; Usual care:; T0 (Baseline): 23.5%; T1 (4 months): 21.3%; T2 (8 months): 25.1%; T3 (12 months): 27.6%; T4 (16 months): 26.2%
Lichtwarck, 2018^42^; 33 nursing homes; 229 patients; Primary outcome: NPI | Quality of Life in Late-stage Dementia; Lower=better; 8 weeks; 12 weeks | Baseline; TIME intervention mean: 28.6 (95% CI [26.7, 30.4]); Brief education-only intervention mean: 29.4 (95% CI [27.6, 31.2]); 8- week follow-up; TIME intervention mean: 28.5 (95% CI [26.6, 30.4]); Brief education-only intervention mean: 29 (95% CI [27.2, 30.8]); Standardized mean difference: −0.03 (p value 0.691); 12 week follow-up; TIME intervention mean: 27.2 (95% CI [25.3, 29.1]); Brief education-only intervention mean: 29.6 (95% CI [27.8, 31.5]); Standardized mean difference: 0.17 (p value 0.044)
Klapwijk, 2017^102^; 12 nursing homes; 288 patients; Primary outcome: CMAI | QOL- Care Relationship; Higher=better; 3 months; 6 months | Baseline to 3 months; STA OP! vs usual care regression coefficient: 0.19 (SE=0.21) (95% CI [−0.22, 0.61]); 3 months to 6 months; STA OP! vs usual care regression coefficient: 0.03 (SE=0.22) (95% CI [−0.4, 0.47])
Klapwijk, 2017^102^; 12 nursing homes; 288 patients; Primary outcome: CMAI | QOL- Positive Affect; Higher=better; 3 months; 6 months | Baseline to 3 months; STA OP! vs usual care regression coefficient: 0.06 (SE=0.31) (95% CI [−0.55, 0.66]); 3 months to 6 months; STA OP! vs usual care regression coefficient: −0.21 (SE=0.32) (95% CI [−0.84, 0.43])
Klapwijk, 2017^102^; 12 nursing homes; 288 patients; Primary outcome: CMAI | QOL- Negative Affect; Higher=better; 3 months; 6 months | Baseline to 3 months; STA OP! vs usual care regression coefficient: 0.27 (SE=0.18) (95% CI [−0.07, 0.62)]; 3 months to 6 months; STA OP! vs usual care regression coefficient: −0.1 (SE=0.19) (95% CI [−0.47, 0.26])
Klapwijk, 2017^102^; 12 nursing homes; 288 patients; Primary outcome: CMAI | QOL- Restless tense behavior; Higher=better; 3 months; 6 months | Baseline to 3 months; STA OP! vs usual care regression coefficient: 0.95 (SE=0.3) (95% CI [0.36, 1.54]); 3 months to 6 months; STA OP! vs usual care regression coefficient: −0.98 (SE=0.32) (95% CI [−1.6, −0.36])
Klapwijk, 2017^102^; 12 nursing homes; 288 patients; Primary outcome: CMAI | QOL- Social relations; Higher=better; 3 months; 6 months | Baseline to 3 months; STA OP! vs usual care regression coefficient: 0.45 (SE=0.24) (95% CI [−0.02, 0.91]); 3 months to 6 months; STA OP! vs usual care regression coefficient: 0.23 (SE=0.25) (95% CI [−0.26, 0.72])
Klapwijk, 2017^102^; 12 nursing homes; 288 patients; Primary outcome: CMAI | QOL- Social isolation; Higher=better; 3 months; 6 months | Baseline to 3 months; STA OP! vs usual care regression coefficient: 0.01 (SE=0.26) (95% CI [−0.49, 0.51]); 3 months to 6 months; STA OP! vs usual care regression coefficient: 0.64 (SE=0.27) (95% CI [0.12, 1.17])
Moniz-Cook, 2017^62^; 63 care homes; 832 patients randomized; Primary outcome: NPI | EQ-5D index; Higher=better; 4 months; 7 months | Staff e-learning vs usual care mean difference in score: 0.08 (95% CI [0.00, 0.16])
Moniz-Cook, 2017^62^; 63 care homes; 832 patients randomized; Primary outcome: NPI | EQ-5D VAS; Higher=better; 4 months; 7 months | Staff e-learning vs usual care mean difference in score: 0.35 (95% CI [−1.58, 1.98])
Moniz-Cook, 2017^62^; 63 care homes; 832 patients randomized; Primary outcome: NPI | QOL-AD; Higher=better; 4 months; 7 months | Staff e-learning vs usual care mean difference in score: 0.2 (95% CI [−1.17, 2.43])
Chenoweth, 2014^82^; 38 clusters; 601 patients randomized; Primary outcome: NR | DEMQOL; Higher=better; 6 months; 8 months | Baseline; Person centered care mean: 99 (95% CI [96, 101]); Usual care and usual environment mean: 101 (95% CI [98, 104]; 6 month follow-up; Person centered care mean: 103 (95% CI [100, 106]); Usual care and usual environment mean: 100 (95% CI [97, 104]); 8-month follow-up; Person centered care mean: 106 (95% CI [103, 110]); Usual care and usual environment mean: 103 (95% CI [99, 106]); Person-centered care vs usual care and usual environment p value: 0.17
Chenoweth, 2009^84^; 15 care sites; 289 patients randomized; Primary outcome: CMAI | QUALID; Lower=better; 4 months; 8 months | Baseline; Person-centered care: 22.7 (SD=2.2); Dementia-care mapping: 23.5 (SD=1.6); Usual care: 23.2 (SD=1.7); 4-month follow-up; Person-centered care: 21.5 (SD=2.2; Dementia-care mapping: 23.4 (SD=1.6); Usual care: 23.7 (SD=1.7); 8-month follow-up; Person-centered care: 20.8 (SD=2.2); Dementia-care mapping: 24.5 (SD=1.6); Usual care: 24.4 (SD=1.7); Arm x time interaction p value: 0.33
van de Ven, 2013^48^; 14 care homes; 268 patients randomized; Primary outcome: CMAI | QOL-Qualidem; Higher=better; 4 months; 8 months | Baseline; Dementia care mapping: 64.52 (SD=2.06); Usual care: 66.31 (SD=1.71); 4 month follow up; Dementia care mapping: 61.88 (SD=2.1); Usual care 63.72 (SD=1.81); 8 month follow up; Dementia care mapping: 64.11 (SD=1.88); Usual care 62.45 (SD=2.19); Arm x time interaction p value 0.995
van de Ven, 2013^48^; 14 care homes; 268 patients randomized; Primary outcome: CMAI | QOL-EuroQOL; Higher=better; 4 months; 8 months | Baseline; Dementia care mapping: 0.39 (SD=0.03); Usual care: 0.44 (SD=0.02); 4 month follow up; Dementia care mapping: 0.34 (SD=0.03); Usual care: 0.41 (SD=0.02); 8 month follow up; Dementia care mapping: 0.35 (SD=0.03); Usual care: 0.36 (SD=0.02); Arm x time interaction p value 0.087
Ballard, 2018^40^; 69 clusters; 832 patients randomized; Primary outcome: QOL | DEMQOL-Proxy; Higher=better; 9 months | WHELD (staff training in person-centered care) vs treatment as usual; mean difference: 2.54 (SE=0.88) (95% CI [0.81, 4.28]) (p value 0.0042)
Rokstad, 2013^60^; 15 nursing homes; 624 patients randomized; Primary outcome: BARS | QUALID; Lower=better; 11 months | Baseline; Dementia care mapping mean: 20.4 (SD=6.8); VPM mean: 21.5 (SD=7); Control mean: 20 (SD=6.6); 11 months; Dementia care mapping mean: 21.4 (SD=7.2); VPM mean: 23.1 (SD=7.5); Control mean: 22.8 (SD=7.4); Dementia care mapping vs control regression coefficient: −3 (95% CI [−5.5, −0.6]) (p value 0.02); VPM vs control regression coefficient: −1.3 (95% CI [−3.4, 0.9]) (p value 0.02)
Fossey, 2006^55^; 12 nursing homes; 346 patients randomized; Primary outcome: neuroleptic use | Wellbeing; Higher=better; 12 months | Training and staff support vs usual care; weighted mean difference: −0.2 (95% CI [−0.5, 0.2]) (p value 0.29)

## PEER REVIEW COMMENTS AND RESPONSES

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes
2 | 2 | Yes
3 | 3 | Yes
4 | 4 | No - Objectives and scope are not clear, but methods are. See additional comments | We have addressed relevant comments below.
5 | 5 | Yes
6 | 6 | Yes
7 | 7 | Yes
8 | 8 | Yes
9 | 9 | Yes
Is there any indication of bias in our synthesis of the evidence?
10 | 1 | No
11 | 2 | No
12 | 3 | No
13 | 4 | No
14 | 5 | No
15 | 6 | No
16 | 7 | No
17 | 8 | No
18 | 9 | No
Are there any published or unpublished studies that we may have overlooked?
19 | 1 | No
20 | 2 | No
21 | 3 | Yes - Although patient distress may solely be a manifestation of dementia or a psychiatric condition, it is likely that previous trauma plays a role in distress in many of these patients. Indeed, it is likely that there is a strong interaction between trauma, both military and non-military, and dementia or other psychiatric conditions (besides PTSD) in driving patient distress. There is an extensive body of literature on trauma-informed care and its efficacy. This should be considered in such a review. | We recognize the significance of trauma as associated with patient distress and acknowledge that past adverse life experiences and trauma may interact or exacerbate distress. Based on our review, we did not identify any studies that explored the issue of the role of trauma in distress behaviors as we defined it for purposes of the review. While trauma-informed care literature could be informative, it is beyond the scope of this review. This area could be valuable for future research in improving distress behavior management, which we’ve noted in our limitations.; We have added mention of this in the limitations including acknowledging that in the military population trauma likely interacts with patient distress among older Veterans (Limitations section, third paragraph). In addition, we noted in the future research section (first paragraph) the need to explore interventions incorporating trauma-informed care principles.
22 | 4 | No
23 | 5 | No
24 | 6 | Yes - - What was your definition for staff-focused person centered interventions? Many person-centered/focused interventions need staff facilitation. I was wondering how you identified that the staff/team was the primary point of deployment as stated in the review criteria. This would help understand how many interventions were not included (sensory stim, reminiscence).; - Also, did you think about including environment centered interventions only in the review? Or no because this is not typically within staff-action? or because this cannot be randomized?; - A study regarding STAR-VA impact on psychotropic medications could be mentioned - McConeghy KW, Curyto K, Jedele J, Intrator O, Karel M, Wiechers I. (2021). Impact of the STAR-VA interdisciplinary behavioral intervention program on psychotropic drug utilization in VA community living centers. Journal of Gerontological Nursing, 42(6), 1522–1540. 10.1016/j.gerinurse.2021.10.009 | We used the following overarching definition for eligible interventions: “Intervention must be primarily targeted at the health care providers or unit (eg, team, clinical service) as the primary point of deployment that involves a change in the way care is delivered.” We acknowledge that some patient focused interventions likely required staff facilitation, but if it was not articulated in the article or was a minor component in the description of the intervention then we did not include it. We identified studies with “patient-centered” interventions based on the labeling used by the study authors.; We did not include interventions that focused solely on changes to the environment because they did not meet our eligibility criteria for being “primarily targeted at the health care providers or unit as the primary point of deployment.”; We have added references to the McConeghy study in the VA studies section.
25 | 7 | No
26 | 8 | No
27 | 9 | No
Additional suggestions or comments can be provided below.
28 | 1 | Thank you for this evidence synthesis. The conclusions validated what I suspected would be found - interventions are required at multiple levels, training/implementation must be consistent and interventions must be customized to the patient. I appreciate how difficult this must have been because of the wide variety of measures, outcomes and interventions. We have a start but a long way to go with this research. | You are welcome.
29 | 2 | Please correct my credentials Maureen Haske-Palomino DNP, MSN, GNP-BC | Apologies – we have made this correction.
30 | 2 | Very complicated topic with so many variables. I initially was worried that it would be hard to capture the importance of the environment, interprofessional and person-centered approaches. I think the panel did a great job pulling the evidence together and hitting on those points. I agree so much more work needs to be done to better understand the impact of distressing behaviors on burnout, utilization, and safety. | Thank you.
31 | 3 | Within the document I am listed as “Chief Strategy Officer” in the section titled “Technical Expert Panel”. That is not correct. I am the Chief of the Division of Hospital Medicine. | Apologies – we have made this correction.
32 | 4 | 1. In Key Findings, many terms do not stand alone. They are not clear until full report is read. The intervention categories of health care team-only, patient-only component, both health care worker and patient focused components are not clear. Most readers will not what these mean and that all of these are under the umbrella of models of health care.; The term “patient-only component” is very confusing given all of the interventions are health care deliver models. In addition, need consistency and more definition of this term.; Later in report referred to as “patient care patterns”; Need to define “health care delivery models” in Key Findings; Need to better define setting of interventions in Key Findings.; First bullet in Key Findings includes a phrase/term that needs more definition, “..along side structured patient care activities” | We agree that we need to make clear definitions of the category labels we have used and be consistent throughout. We have added definitions for these categories in the Executive Summary (Current Review section, 4^th^ paragraph). We have also revised the identified language throughout in need of clarification.
33 | 4 | 2. Is there a difference between “health care delivery models” and “staff-focused” interventions ((line 37, pg ix)? In not, “staff-focused” interventions is a much clearer, self-evident term. It they are different, then they each need to be defined and differences highlighted. I like on how page ix, line 31, the interventions are summarized as “interventions centered on staff action (eg, optimal staffing, staffing education/training, staff approaches to improved patient care management). I suggest using this definition and nomenclature rather than “health care deliver models”. | For clarity, we have dropped the phrase “health care delivery models” from the report and stick to using “health care team-focused interventions.” We elected to use the term “health care team” instead of staff to draw a distinction from terms used when discussing the outcomes (eg, “staff level”).
34 | 4 | 3. The outcome of interest needs to be better defined and referred to more consistently. Is the outcome of interest?; Behavioral and psychological symptoms (line 55, pg viii); Patient distress and associated behaviors ((line 7, pg ix); Distress, or disruptive, behaviors (line 10, pg ix); Distress behaviors (line30, pg ix); Persistent or recurrent distress and/or disrupted behaviors (line 38, pg ix) | We appreciate the need for clarity on the label and definition of the primary outcome of interest. We have now identified “distress behaviors” as the primary outcome and defined it as well as acknowledge that many of the included studies use a variety of labels and language to mean the same behavioral construct (Introduction section, paragraph 5).
35 | 4 | 4. None of the terms listed in #3 are clear. It would be more useful to list out specific behaviors that are included and not included. For example, would patients with depressive symptoms along be included? Psychotic symptoms alone? Wandering alone? | As noted above, we have clarified our definition of distress behaviors including naming specific relevant behaviors and then use this term with all identified by our search. Individual studies had a variety of definitions and examples for such behaviors so it would be unwieldly to describe every potential behavior included by each included study. We have also noted this in the limitations.
36 | 4 | 5. Need to better define and perhaps list out all of settings that meet criteria for “post acute”. Becomes much clearer on page 6, but should be clear before reader reaches this point (if they ever do). | We have clarified the criteria for “post-acute” as recommended to be: “long-term residential or inpatient health care settings”
37 | 4 | 6. Would be much clearer to limit sample to older adults with dementia. The inclusion of persons with serious mental illness and other psychiatric disorders (line 27, pg ix) makes interpreting findings difficult. How many studies were included that did not predominately include persons with dementia? Most persons understand what distressing and disruptive behaviors are when referring to persons with dementia, but this term is much less familiar and clear when use in reference to persons with serious mental illness and other psychiatric disorders. In addition, it is not clear why older adult was defined as 50 years or older. Interpretations are challenging given wide range in age, diagnosis/sx eligibility criteria, intervention components, setting and outcomes. | We purposefully did not limit the sample to studies focused on older adults with dementia on the recommendation of the nominating partners so that we could identify potentially effective interventions from other patient populations. In the end, all the studies for post-acute settings focused primarily on patients with dementia. The definition of older adult was defined as 50 years based on recommendations from our nominating partners and technical expert panel. However, we agree that the diversity across patient populations make conclusions more challenging. We have noted this in the limitations. We have also included the mean age range of the participants in the evidence profile table.
38 | 4 | 7. I do not care for or understand the term “complex older adult” (line 9, pgxiii). | We have dropped the term “complex.”
39 | 4 | 8. “just targeting patterns of patient care” (line 41, pg xii) is not a clear term. | This phrase has been rewritten to read: “focused on delivering individual patient care treatments.”
40 | 4 | 9. Need to remove term, “dementia patient” across report. Replace with persons or individuals with dementia. | We have replacement this term as recommended.
41 | 5 | Question about title of the report, which we discussed and tweaked several times. Per last communication, the title was “Care for Older Adults with Distress Behaviors: Health Care Team Focused Interventions” which seems to capture a bit better the essence of the review than the current title, “Health Care Delivery Models for the Management of Patient Distress.” The current title doesn’t get at the key issue of “behaviors” (i.e., distress can include anxiety, depression, fear, grief, etc, that doesn’t manifest in distressed/disruptive behaviors that interfere with care, etc. Perhaps “Care for Older Adults with Distress Behaviors: Health Care Delivery Models”? | We have changed the title to “Care for Older Adults with Distress Behaviors: Health Care Team Focused Interventions” as originally discussed. We are avoiding the phrase “health care delivery models” on reviewer recommendations as noted above.
42 | 5 | Perhaps address in methods why we chose not to include Inpatient Medicine setting of care, as many readers may be interested in that context | We did not exclude studies that were conducted in inpatient medicine setting; however, we did not identify any studies otherwise meeting our inclusion criteria that were conducted in the inpatient medicine setting. It is possible that our search terms did not identify relevant studies in that setting. We have adjusted the language throughout to make this clarification and noted this in the limitations.
43 | 5 | Perhaps a bit more about challenges (and insufficiency…) of research in this area? Limitations section is excellent, including acknowledgement of staff turnover as a real challenge for implementing/studying these interventions. I also wonder about looking only at average scores between groups and/or pre-post. Is there missing information to look at variability of impact, by looking at individual trajectories? How do we understand for which patients interventions appeared to have more positive impact vs for those who did not benefit? | We agree that intervention effects are likely not consistent for all patients and more work is needed to understand how patients with different types of distress behaviors and health histories (ie, PTSD) might respond differently to such interventions once effectiveness is established. We have added this consideration to the Future Research Section.
44 | 5 | Did we miss important literature by not including workplace violence or Prevention and Management of Disruptive Behavior (PMDB) studies, targeted at this population? (maybe we did include, or maybe they just don’t exist…) | We did not include search terms for workplace violence after discussion with the technical expert panel and with consideration for scope of this review. We agree that there is potentially relevant literature in that area. We have noted this in the limitations.; We believe that we would have picked up articles on prevention and management of disruptive behavior if they were in the published literature as we included search terms for “disruptive behavior.”
45 | 5 | Note that I have some minor editing suggestions that I will send directly to Dr. Goldstein via pdf document, rather than try to outline here, which would be cumbersome and not fit within the character count. | Thank you for sharing these suggestions. We have address them directly in the final draft.
46 | 6 | I liked how the review grouped interventions by intervention focus components and multi component interventions.; Recommendations:; 1) In the objectives behaviors described as challenging or disruptive were the focus - disruptive/challenging to who? How is this different than how distress/distressed behavior is defined? I would recommend defining these terms and using distress behaviors which is more person-centered language, unless a study was making a specific point about level of challenge/disruption and to whom. | Thank you. We are glad that this resonated with the reviewer.; We appreciate this observation and have changed the language throughout to distress behaviors as noted above in comment # 34.
47 | 6 | 2) Use person-centered language when possible, such as use person or resident in place of patient, distress behaviors instead of disruptive behaviors, etc. | We have adjusted the language in the report to be patient-centered as recommended.
48 | 6 | 3) Clearer language about interventions which all focus on staff-action, and also have multiple labels such as a) person-centered and patient-facing interventions, b) staff-facing, staff-focused, HCW interventions, and c) clinic-facing, unit level, unit focused interventions. It was hard as reader to try to keep track of which we were talking about.; - Maybe: a) person centered interventions, b) staff centered interventions, c) person and staff centered interventions, d) person, staff, and environment centered interventions. | We have clarified the intervention language as noted above in response to comment #32.
49 | 6 | 4) Be sure you define acronyms the first time they are used (KQ, ROB) | We have reviewed the report to make sure that acronyms were defined with first time use.
50 | 6 | 5) I would have also liked to see a table listing the results for person centered/focused interventions and staff/person/environment centered/focused interventions, similar to table 2 for staff centered/focused interventions and table 3 for staff and person centered interventions.; Thanks for putting together this important resource. | These tables have been added as requested.
51 | 7 | well done-very thorough | Thank you.
52 | 8 | • Document page ix, Line 14 (overall page 13): recommend further defining short stay | We have defined short stay as requested.
53 | 8 | • Document page ix, Line 31 (overall page 13): recommend changing “staff action” to “staffing characteristics” | This change has been made as suggested.
54 | 8 | • Document page x, Line 18 (overall page 14): recommend identifying what was used to measure quality of life | We have clarified that the measures used to assess quality of life varied. We prioritized EuroQOL when possible.
55 | 8 | • Document page x, Line 21 (overall page 14): spell out ROB abbreviation | ROB has been spelled out as risk of bias.
56 | 8 | • Document page x, Line 55 (overall page 14): spell out CI abbreviation | We ended up removing this reference due to other edits.
57 | 8 | • Document page xii, Line 58 (overall page 16): After “higher system-level targets (e.g., supervisory involvement, facility culture) could be explored.” Add: “In addition, discipline specific interventions such as the use of Social Workers for intervention and patient-centered care approaches could be explored.” | We have made this addition as recommended.
58 | 8 | • Document page 6, Line 16 (overall page 23): Exclusion “Patients with delirium” - consider adding additional details such as “primary diagnosis of delirium” or “patients with co-occurring delirium” - how was delirium itself controlled for and excluded from this review/study? | We have clarified this exclusion criteria to be “patients with primary diagnosis of delirium.” It is possible that patients included in eligible studies also had delirium, but this was not reported. We only excluded those studies that specifically targeted patients primarily identified to have delirium as the source of their distress behavior.
59 | 9