# ABBREVIATIONS TABLE

Abbreviation: Definition
ABMI: Agitation behavior mapping instrument
AICT: Advanced illness care team
BC: Behavioral coordinator
CBS: Challenging Behavior Scale
CI: Confidence interval
CLC: Community living centers
CMAI: Cohen-Mansfield Agitation Inventory
DCM: Dementia care mapping
EPOC: Effective Practice and Organisation of Care
FBFC-CI: Function and Behavior Focused Care for the Cognitively Impaired
FFC-AL-EIT: Function Focused Care for Assisted Living Using the Evidence Integration Triangle
FFC-CI: Function Focused Care Intervention for the Cognitively Impaired
GRADE: Grading of Recommendations Assessment, Development and Evaluation
HCW: Health care worker
HR: Hazard ratio
ICC: Intraclass correlation coefficient
ICU: Intensive care unit
IDD: Intellectual and developmental disabilities
KQ: Key question
MBI: Maslach Burnout Inventory
MD: Mean difference
NPI: Neuropsychiatric Inventory
OECD: Organization for Economic Co-operation and Development
OPAL: Optimizing Prescribing of Antipsychotics in Long-Term Care
OR: Odds ratio
PCC: Person-centered care
PTSD: Posttraumatic stress disorder
QOL: Quality of life
QUALID: Quality of Life in Late-Stage Dementia
RAI-MDS: Resident Assessment Instrument-Minimum Dataset
RCT: Randomized controlled trial
RN: Registered nurse
ROB: Risk of bias
SD: Standard deviation
SE: Standard error
SMD: Standardized mean difference
SMI: Serious mental illness
STAR: Staff Training in Assisted Living Residences
STI: Serial Trial Intervention
SUD: Substance use disorder
TREA: Treatment Routes for Exploring Agitation
UC: Usual care
WHELD: Well-being and Health for People Living with Dementia