# References

1 Colello K, SV. P. Congressional Research Service Report: Long-Term Care Services for Veterans. 2017;https://fas.org/sgp/crs/misc/R44697.pdf.
2 Department of Veterans Affairs. Budget in Brief. 2020;https://www.va.gov/budget/docs/summary/fy2020VAbudgetInBrief.pdf.
3 Van Houtven CH, Smith VA, Stechuchak KM, . Comprehensive Support for Family Caregivers: Impact on Veteran Health Care Utilization and Costs. Med Care Res Rev. 2019;76(1):89–114.29148338
4 U.S. Congress. VA MISSION Act of 2018.https://www.congress.gov/115/bills/s2372/BILLS-115s2372enr.pdf.
5 Ramchand R, Tanielian T, Fisher MP, . Hidden heroes: America’s military caregivers. Rand Corporation; 2014.
6 Department of Veterans Affairs. Veterans’ Families, Caregivers, and Survivors Federal Advisory Committee Planning Meeting Minutes. October 23–24 2017;https://www.va.gov/ADVISORY/docs/Minutes-VFCSACOct2017.pdf.
7 Department of Veterans Affairs. VA Geriatrics and Gerontology Advisory Committee Meeting Minutes. October 23–24 2017;https://www.va.gov/ADVISORY/docs/Minutes-GGACOct2017.docx.
8 Van Houtven CH, Miller KEM, O’Brien EC, . Development and Initial Validation of the Caregiver Perceptions About Communication With Clinical Team Members (CAPACITY) Measure. Med Care Res Rev. 2017:1077558717747985.29262757
9 Andersen RM. Revisiting the behavioral model and access to medical care: does it matter? J Health Soc Behav. 1995:1–10.
10 Greene VL, Ondrich JI. Risk factors for nursing home admissions and exits: a discrete-time hazard function approach. J Gerontol. 1990;45(6):S250–258.2229951
11 Deimling GT, Poulshock SW. The transition from family in-home care to institutional care. Focus on health and attitudinal issues as predisposing factors. Res Aging. 1985;7(4):563–576.4095381
12 Lawton MP. Environment and other determinants of weil-being in older people. Gerontologist. 1983;23(4):349–357.6352420
13 Wahl HW, Iwarsson S, Oswald F. Aging well and the environment: toward an integrative model and research agenda for the future. Gerontologist. 2012;52(3):306–316.22419248
14 Flaskerud JH, Winslow BJ. Conceptualizing vulnerable populations health-related research. Nurs Res. 1998;47(2):69–78.9536190
15 Shea BJ, Reeves BC, Wells G, . AMSTAR 2: a critical appraisal tool for systematic reviews that include randomised or non-randomised studies of healthcare interventions, or both. BMJ. 2017;358:j4008.28935701
16 Apostolo J, Cooke R, Bobrowicz-Campos E, . Predicting risk and outcomes for frail older adults: an umbrella review of frailty screening tools. JBI Database System Rev Implement Rep. 2017;15(4):1154–1208.
17 Kojima G. Frailty as a Predictor of Nursing Home Placement Among Community-Dwelling Older Adults: A Systematic Review and Meta-analysis. J Geriatr Phys Ther. 2018;41(1):42–48.27341327
18 Sternberg SA, Wershof Schwartz A, Karunananthan S, Bergman H, Mark Clarfield A. The identification of frailty: a systematic literature review. J Am Geriatr Soc. 2011;59(11):2129–2138.22091630
19 Vermeiren S, Vella-Azzopardi R, Beckwee D, . Frailty and the Prediction of Negative Health Outcomes: A Meta-Analysis. J Am Med Dir Assoc. 2016;17(12):1163 e1161–1163 e1117.
20 Black W, Almeida OP, Black W, Almeida OP. A systematic review of the association between the Behavioral and Psychological Symptoms of Dementia and burden of care. Int Psychogeriatr. 2004;16(3):295–315.15559754
21 Burridge L, Winch S, Clavarino A. Reluctance to care: a systematic review and development of a conceptual framework. Cancer Nurs. 2007;30(2):E9–19.17413772
22 Cepoiu-Martin M, Tam-Tham H, Patten S, Maxwell CJ, Hogan DB. Predictors of long-term care placement in persons with dementia: a systematic review and meta-analysis. Int J Geriatr Psychiatry. 2016;31(11):1151–1171.27045271
23 Frazier SC. Health outcomes and polypharmacy in elderly individuals: an integrated literature review. J Gerontol Nurs. 2005;31(9):4–11.
24 Gawel J, Vengrow D, Collins J, Brown S, Buchanan A, Cook C. The short physical performance battery as a predictor for long term disability or institutionalization in the community dwelling population aged 65 years old or older. Physical Therapy Reviews. 2013;17(1):37–44.
25 Lehmann J, Michalowsky B, Kaczynski A, . The Impact of Hospitalization on Readmission, Institutionalization, and Mortality of People with Dementia: A Systematic Review and Meta-Analysis. J Alzheimers Dis. 2018;64(3):735–749.29966191
26 Luppa M, Luck T, Brahler E, Konig HH, Riedel-Heller SG. Prediction of institutionalisation in dementia. A systematic review. Dement Geriatr Cogn Disord. 2008;26(1):65–78.18617737
27 Luppa M, Luck T, Weyerer S, Konig HH, Brahler E, Riedel-Heller SG. Prediction of institutionalization in the elderly. A systematic review. Age Ageing. 2010;39(1):31–38.19934075
28 Luppa M, Luck T, Weyerer S, Konig HH, Riedel-Heller SG. Gender differences in predictors of nursing home placement in the elderly: a systematic review. Int Psychogeriatr. 2009;21(6):1015–1025.19589192
29 O’Caoimh R, Cornally N, Weathers E, . Risk prediction in the community: A systematic review of case-finding instruments that predict adverse healthcare outcomes in community-dwelling older adults. Maturitas. 2015;82(1):3–21.25866212
30 Palmer JL, Langan JC, Krampe J, . A model of risk reduction for older adults vulnerable to nursing home placement. Res Theory Nurs Pract. 2014;28(2):162–192.25087327
31 Pamoukdjian F, Paillaud E, Zelek L, . Measurement of gait speed in older adults to identify complications associated with frailty: A systematic review. J Geriatr Oncol. 2015;6(6):484–496.26362356
32 Rydwik E, Bergland A, Forsen L, Frandin K. Investigation into the reliability and validity of the measurement of elderly people’s clinical walking speed: a systematic review. Physiother Theory Pract. 2012;28(3):238–256.21929322
33 Snowden MB, Steinman LE, Bryant LL, . Dementia and co-occurring chronic conditions: a systematic literature review to identify what is known and where are the gaps in the evidence? Int J Geriatr Psychiatry. 2017;32(4):357–371.28146334
34 Suchowersky O, Reich S, Perlmutter J, Zesiewicz T, Gronseth G, Weiner WJ. Appendix A: Practice parameter: Diagnosis and prognosis of new onset Parkinson disease (an evidence-based review): Report of the Quality Standards Subcommitte of the American Academy Neurology. CONTINUUM Lifelong Learning in Neurology. 2007;13(1):158–165.
35 Torti FM, Jr., Gwyther LP, Reed SD, Friedman JY, Schulman KA. A multinational review of recent trends and reports in dementia caregiver burden. Alzheimer Dis Assoc Disord. 2004;18(2):99–109.15249854
36 Beswick AD, Gooberman-Hill R, Smith A, Wylde V, Ebrahim S. Maintaining independence in older people. Rev Clin Gerontol. 2010;20(2):128–153.
37 Berthelsen CB, Kristensson J. The content, dissemination and effects of case management interventions for informal caregivers of older adults: a systematic review. Int J Nurs Stud. 2015;52(5):988–1002.25661314
38 Cochrane A, Furlong M, McGilloway S, Molloy DW, Stevenson M, Donnelly M. Time-limited home-care reablement services for maintaining and improving the functional independence of older adults. Cochrane Database Syst Rev. 2016;10:CD010825.27726122
39 Pimouguet C, Lavaud T, Dartigues JF, Helmer C. Dementia case management effectiveness on health care costs and resource utilization: a systematic review of randomized controlled trials. J Nutr Health Aging. 2010;14(8):669–676.20922344
40 Reilly S, Miranda-Castillo C, Malouf R, . Case management approaches to home support for people with dementia. Cochrane Database Syst Rev. 2015(1):CD008345.
41 Tam-Tham H, Cepoiu-Martin M, Ronksley PE, Maxwell CJ, Hemmelgarn BR. Dementia case management and risk of long-term care placement: a systematic review and meta-analysis. Int J Geriatr Psychiatry. 2013;28(9):889–902.23188735
42 You EC, Dunt DR, Doyle C. Case managed community aged care: what is the evidence for effects on service use and costs? J Aging Health. 2013;25(7):1204–1242.23958520
43 Hickman LD, Phillips JL, Newton PJ, Halcomb EJ, Al Abed N, Davidson PM. Multidisciplinary team interventions to optimise health outcomes for older people in acute care settings: A systematic review. Arch Gerontol Geriatr. 2015;61(3):322–329.26255065
44 Dickinson C, Dow J, Gibson G, Hayes L, Robalino S, Robinson L. Psychosocial intervention for carers of people with dementia: What components are most effective and when? A systematic review of systematic reviews. Int Psychogeriatr. 2017;29(1):31–43.27666669
45 Griffin JM, Meis LA, Greer N, . Effectiveness of Caregiver Interventions on Patient Outcomes in Adults With Dementia or Alzheimer’s Disease: A Systematic Review. Gerontol Geriatr Med. 2015;1:2333721415595789.28138460
46 Jensen M, Agbata IN, Canavan M, McCarthy G. Effectiveness of educational interventions for informal caregivers of individuals with dementia residing in the community: systematic review and meta-analysis of randomised controlled trials. Int J Geriatr Psychiatry. 2015;30(2):130–143.25354132
47 Pinquart M, Sorensen S. Helping caregivers of persons with dementia: which interventions work and how large are their effects? Int Psychogeriatr. 2006;18(4):577–595.16686964
48 Smits CH, de Lange J, Droes RM, Meiland F, Vernooij-Dassen M, Pot AM. Effects of combined intervention programmes for people with dementia living at home and their caregivers: a systematic review. Int J Geriatr Psychiatry. 2007;22(12):1181–1193.17457793
49 Vandepitte S, Van Den Noortgate N, Putman K, Verhaeghe S, Faes K, Annemans L. Effectiveness Of Supporting Informal Caregivers Of People With Dementia: A Systematic Review. Value Health. 2015;18(7):A407–408.
50 Van’t Leven N, Prick AE, Groenewoud JG, Roelofs PD, de Lange J, Pot AM. Dyadic interventions for community-dwelling people with dementia and their family caregivers: a systematic review. Int Psychogeriatr. 2013;25(10):1581–1603.23883489
51 Vernooij-Dassen M, Draskovic I, McCleery J, Downs M. Cognitive reframing for carers of people with dementia. Cochrane Database Syst Rev. 2011(11):CD005318.
52 Goy E, Freeman, M., Kanasagara, D. A Systematic Evidence Review of Interventions for Non-professional Caregivers of Individuals with Dementia. VA ESP Report. 2010.
53 Parker D, Mills S, Abbey J. Effectiveness of interventions that assist caregivers to support people with dementia living in the community: a systematic review. In. Vol 6.2. International Journal of Evidence-Based Healthcare 2008:137–172
54 Brown L, Forster A, Young J, . Medical day hospital care for older people versus alternative forms of care. Cochrane Database Syst Rev. 2015(6):CD001730.
55 Du Preez J, Millsteed J, Marquis R, Richmond J. The Role of Adult Day Services in Supporting the Occupational Participation of People with Dementia and Their Carers: An Integrative Review. Healthcare (Basel). 2018;6(2):08.
56 Ellen MEMBAP, Demaio PBA, Lange AP, Wilson MGP. Adult Day Center Programs and Their Associated Outcomes on Clients, Caregivers, and the Health System: A Scoping Review. Gerontologist. 2017;57(6).
57 Fields NL, Anderson KA, Dabelko-Schoeny H. The effectiveness of adult day services for older adults: a review of the literature from 2000 to 2011. J Appl Gerontol. 2014;33(2):130–163.24652952
58 Brueckmann A, Seeliger C, Schlembach D, Schleussner E. PP048. Carotid intima-media-thickness in the first trimester as a predictor of preeclampsia. Pregnancy Hypertens. 2013;3(2):84.
59 Lee H, Cameron MH. Respite care for people with dementia and their carers. Cochrane Database Syst Rev. 2014(1):CD004396.
60 Mason A, Weatherly H, Spilsbury K, . A systematic review of the effectiveness and cost-effectiveness of different models of community-based respite care for frail older people and their carers. Health Technol Assess. 2007;11(15):1–157.
61 Shaw C, McNamara R, Abrams K, . Systematic review of respite care in the frail elderly. Health Technol Assess. 2009;13(20):1–224.
62 Vandepitte S, Van Den Noortgate N, Putman K, Verhaeghe S, Verdonck C, Annemans L. Effectiveness of respite care in supporting informal caregivers of persons with dementia: a systematic review. Int J Geriatr Psychiatry. 2016;31(12):1277–1288.27245986
63 Elkan R, Kendrick D, Dewey M, . Effectiveness of home based support for older people: systematic review and meta-analysis. BMJ. 2001;323(7315):719–725.11576978
64 Markle-Reid M, Browne G, Weir R, Gafni A, Roberts J, Henderson SR. The effectiveness and efficiency of home-based nursing health promotion for older people: a review of the literature. Med Care Res Rev. 2006;63(5):531–569.16954307
65 Mayo-Wilson E, Grant S, Burton J, Parsons A, Underhill K, Montgomery P. Preventive home visits for mortality, morbidity, and institutionalization in older adults: a systematic review and meta-analysis. PLoS ONE. 2014;9(3):e89257.24622676
66 Ploeg J, Feightner J, Hutchison B, Patterson C, Sigouin C, Gauld M. Effectiveness of preventive primary care outreach interventions aimed at older people: meta-analysis of randomized controlled trials. Can Fam Physician. 2005;51:1244–1245.16926937
67 Stuck AE, Egger M, Hammer A, Minder CE, Beck JC. Home visits to prevent nursing home admission and functional decline in elderly people: systematic review and meta-regression analysis. JAMA. 2002;287(8):1022–1028.11866651
68 van Haastregt JC, Diederiks JP, van Rossum E, de Witte LP, Crebolder HF. Effects of preventive home visits to elderly people living in the community: systematic review. BMJ. 2000;320(7237):754–758.10720360
69 Stall N, Nowaczynski M, Sinha SK. Systematic review of outcomes from home-based primary care programs for homebound older adults. J Am Geriatr Soc. 2014;62(12):2243–2251.25371236
70 Totten AM, White-Chu EF, Wasson N, . Home-based primary care interventions. Prepared by the Pacific Northwest Evidence-based Practice Center under Contract No 290-2012-00014-I. 2016(AHRQ Publication No. 15(16)-EHC036-EF. Rockville, MD: Agency for Healthcare Research and Quality).
71 Frost R, Belk C, Jovicic A, . Health promotion interventions for community-dwelling older people with mild or pre-frailty: a systematic review and meta-analysis. BMC Geriatr. 2017;17(1):157.28728570
72 Gine-Garriga MR-FM, Coll-Planas L, Sitja-Rabert M, & Salva A. Correction. Arch Phys Med Rehabil. 2018;99(1):211–212.29289297
73 Guirguis-Blake JM, Michael YL, Perdue LA, Coppola EL, Beil TL. Interventions to Prevent Falls in Older Adults: Updated Evidence Report and Systematic Review for the US Preventive Services Task Force. JAMA. 2018;319(16):1705–1716.29710140
74 Steultjens EM, Dekker J, Bouter LM, Jellema S, Bakker EB, van den Ende CH. Occupational therapy for community dwelling elderly people: a systematic review. Age Ageing. 2004;33(5):453–460.15315918
75 Forbes D, Blake CM, Thiessen EJ, Peacock S, Hawranik P. Light therapy for improving cognition, activities of daily living, sleep, challenging behaviour, and psychiatric disturbances in dementia. Cochrane Database Syst Rev. 2014(2):CD003946.
76 Wulff KD, Cole DG, Clark RL, . Aberration correction in holographic optical tweezers. Opt Express. 2006;14(9):4170–4175.19516566
77 Montgomery P, Mayo-Wilson E, Dennis J. Personal assistance for older adults (65+) without dementia. Cochrane Database Syst Rev. 2008(1):CD006855.
78 Olazaran J, Reisberg B, Clare L, . Nonpharmacological therapies in Alzheimer’s disease: a systematic review of efficacy. Dement Geriatr Cogn Disord. 2010;30(2):161–178.20838046
79 Spijker A, Vernooij-Dassen M, Vasse E, . Effectiveness of nonpharmacological interventions in delaying the institutionalization of patients with dementia: a meta-analysis. J Am Geriatr Soc. 2008;56(6):1116–1128.18410323
80 Van der Roest HG, Wenborn J, Pastink C, Droes RM, Orrell M. Assistive technology for memory support in dementia. Cochrane Database Syst Rev. 2017(6):CD009627.
81 Gilhooly KJ, Gilhooly ML, Sullivan MP, . A meta-review of stress, coping and interventions in dementia and dementia caregiving. BMC Geriatr. 2016;16:106.27193287
82 Johri M, Beland F, Bergman H. International experiments in integrated care for the elderly: a synthesis of the evidence. Int J Geriatr Psychiatry. 2003;18(3):222–235.12642892
83 Hickam DH, Weiss JW, Guise J-M, . Outpatient case management for adults with medical illness and complex care needs. 2013.
84 Rockwood K, Stadnyk K, MacKnight C, McDowell I, Hebert R, Hogan DB. A brief clinical instrument to classify frailty in elderly people. Lancet. 1999;353(9148):205–206.9923878
85 Armstrong JJ, Stolee P, Hirdes JP, Poss JW. Examining three frailty conceptualizations in their ability to predict negative outcomes for home-care clients. Age and aging. 2010;39(6):755–758.
86 Drubbel I, Numans ME, Kranenburg G, Bleijenberg N, de Wit NJ, Schuurmans MJ. Screening for frailty in primary care: a systematic review of the psychometric properties of the frailty index in community-dwelling older people. BMC Geriatr. 2014;14(1):27.24597624
87 Forti P, Rietti E, Pisacane N, Olivelli V, Maltoni B, Ravaglia G. A comparison of frailty indexes for prediction of adverse health outcomes in an elderly cohort. Arch Gerontol Geriatr. 2012;54(1):16–20.21339007
88 Hogan DB, Freiheit EA, Strain LA, . Comparing frailty measures in their ability to predict adverse outcome among older residents of assisted living. BMC Geriatr. 2012;12(1):56.22978265
89 Rockwood K, Song X, MacKnight C, . A global clinical measure of fitness and frailty in elderly people. CMAJ. 2005;173(5):489–495.16129869
90 Rothman MD, Leo-Summers L, Gill TM. Prognostic significance of potential frailty criteria. J Am Geriatr Soc. 2008;56(12):2211–2216.19093920
91 Jones DM, Song X, Rockwood K. Operationalizing a frailty index from a standardized comprehensive geriatric assessment. J Am Geriatr Soc. 2004;52(11):1929–1933.15507074
92 Alessi CA, Josephson KR, Harker JO, Pietruszka FM, Hoyl MT, Rubenstein LZ. The yield, reliability, and validity of a postal survey for screening community-dwelling older people. J Am Geriatr Soc. 2003;51(2):194–202.12558716
93 FitzGerald C, O’Caoimh R, Healy E, . Risk Instrument for Screening in the Community (RISC): predicting adverse outcomes in older adults. Paper presented at: Irish Journal of Medical Science 2014.
94 Roos NP, Roos LL, Mossey J, Havens B. Using administrative data to predict important health outcomes: entry to hospital, nursing home, and death. Med Care. 1988:221–239.3352323
95 St John PD, Montgomery PR. Validity of an early risk score for older adults. J R Coll Physicians Edinb. 2014;44(2):111–115.24999770
96 Brodaty H, Mittelman M, Gibson L, Seeher K, Burns A. The effects of counseling spouse caregivers of people with Alzheimer disease taking donepezil and of country of residence on rates of admission to nursing homes and mortality. Am J Geriatr Psychiatry. 2009;17(9):734–743.19705519
97 Coehlo DP, Hooker K, Bowman S. Institutional placement of persons with dementia: What predicts occurrence and timing? J Fam Nurs. 2007;13(2):253–277.17452605
98 Gaugler JE, Kane RL, Kane RA, Newcomer R. Early community-based service utilization and its effects on institutionalization in dementia caregiving. Gerontologist. 2005;45(2):177–185.15799982
99 Hatoum HT, Thomas SK, Lin S-J, Lane R, Bullock R. Predicting time to nursing home placement based on activities of daily living scores–a modelling analysis using data on Alzheimer’s disease patients receiving rivastigmine or donepezil. J Med Econ. 2009;12(2):98–103.19492974
100 Hébert R, Dubois M-F, Wolfson C, Chambers L, Cohen C. Factors associated with long-term institutionalization of older people with dementia: data from the Canadian Study of Health and Aging. J Gerontol A Biol Sci Med Sci. 2001;56(11):M693–M699.11682577
101 Heyman A, Peterson B, Fillenbaum G, Pieper C. Predictors of time to institutionalization of patients with Alzheimer’s disease: the CERAD experience, part XVII. Neurology. 1997;48(5):1304–1309.9153462
102 Kales HC, Chen P, Blow FC, Welsh DE, Mellow AM. Rates of clinical depression diagnosis, functional impairment, and nursing home placement in coexisting dementia and depression. Am J Geriatr Psychiatry. 2005;13(6):441–449.15956263
103 Knopman DS, Berg J, Thomas R, Grundman M, Thal L, Sano M. Nursing home placement is related to dementia progression Experience from a clinical trial. Neurology. 1999;52(4):714–714.10078715
104 Miller SC, Prohaska TR, Furner SE, Freels S, Brody JA, Levy PS. Time to nursing home admission for persons with Alzheimer’s disease: the effect of health care system characteristics. J Gerontol B Psychol Sci Soc Sci. 1998;53(6):S341–353.9826976
105 Pot AM, Deeg DJ, Knipscheer CP. Institutionalization of demented elderly: the role of caregiver characteristics. Int J Geriatr Psychiatry. 2001;16(3):273–280.11288161
106 Scott WK, Edwards KB, Davis DR, Cornman CB, Macera CA. Risk of institutionalization among community long-term care clients with dementia. Gerontologist. 1997;37(1):46–51.9046705
107 Wattmo C. Long Term Outcome and Prediction Models of Cognition, Activities of Daily Living and Nursing Home Placement in Alzheimer’s Disease with Cholinesterase Inhibitor Treatment. Lund University, Faculty of Medicine Doctoral Dissertation Series. 2011;2011(75).
108 Yaffe K, Fox P, Newcomer R, . Patient and caregiver characteristics and nursing home placement in patients with dementia. JAMA. 2002;287(16):2090–2097.11966383
109 Young RF. Nursing home admission of female Alzheimer’s patients: family care aspects. J Women’s Health Issues. 2003;13(1):2–7.
110 Andel R, Hyer K, Slack A. Risk factors for nursing home placement in older adults with and without dementia. Journal of Aging Health. 2007;19(2):213–228.17413132
111 Andrieu S, Reynish W, Nourhashemi F, . Nutritional risk factors for institutional placement in Alzheimer’s disease after one year follow-up. J Nutr Health Aging. 2001;5(2):113–117.11426292
112 Baek J. Individual variations in family caregiving over the caregiving career, Pennsylvania State University; 2004.
113 Banerjee S, Murray J, Foley B, Atkins L, Schneider J, Mann A. Predictors of institutionalisation in people with dementia. J Neurol Neurosurg Psychiatry. 2003;74(9):1315–1316.12933944
114 Buhr GT, Kuchibhatla M, Clipp EC. Caregivers’ reasons for nursing home placement: clues for improving discussions with families prior to the transition. Gerontologist. 2006;46(1):52–61.16452284
115 Dorenlot P, Harboun M, Bige V, Henrard JC, Ankri J. Major depression as a risk factor for early institutionalization of dementia patients living in the community. International Journal of Geriatric Psychiatry: A journal of the psychiatry of late life allied sciences. 2005;20(5):471–478.
116 Gaugler JE, Edwards AB, Femia EE, . Predictors of institutionalization of cognitively impaired elders: family help and the timing of placement. J Gerontol B Psychol Sci Soc Sci. 2000;55(4):P247–255.11584881
117 Gilley DW, Bienias JL, Wilson RS, Bennett DA, Beck TL, Evans DA. Influence of behavioral symptoms on rates of institutionalization for persons with Alzheimer’s disease. Psychol Med. 2004;34(6):1129–1135.15554582
118 Kopetz S, Steele CD, Brandt J, . Characteristics and outcomes of dementia residents in an assisted living facility. Int J Geriatr Psychiatry. 2000;15(7):586–593.10918338
119 Lopez OL, Becker JT, Chang Y-F, . The long-term effects of conventional and atypical antipsychotics in patients with probable Alzheimer’s disease. Am J Psychiatry. 2013;170(9):1051–1058.23896958
120 O’Donnell BF, Drachman DA, Barnes HJ, Peterson KE, Swearer JM, Lew RA. Incontinence and troublesome behaviors predict institutionalization in dementia. J Geriatr Psychiatry Neurol. 1992;5(1):45–52.1571074
121 Rongve A, Vossius C, Nore S, Testad I, Aarsland D. Time until nursing home admission in people with mild dementia: comparison of dementia with Lewy bodies and Alzheimer’s dementia. Int J Geriatr Psychiatry. 2014;29(4):392–398.23943275
122 Spijker A, Wollersheim H, Teerenstra S, . Systematic care for caregivers of patients with dementia: a multicenter, cluster-randomized, controlled trial. Am J Geriatr Psychiatry. 2011;19(6):521–531.21358385
123 Whitlatch CJ, Feinberg LF, Stevens EJ, Aging. Predictors of institutionalization for persons with Alzheimer’s disease and the impact on family caregivers. J Ment Health. 1999;5(3):275–288.
124 Williams MM, Xiong C, Morris JC, Galvin JE. Survival and mortality differences between dementia with Lewy bodies vs Alzheimer disease. Neurology. 2006;67(11):1935–1941.17159097
125 Kunik ME, Snow AL, Davila JA, . Consequences of aggressive behavior in patients with dementia. J Neuropsychiatry Clin Neurosci. 2010;22(1):40–47.20160208
126 Gibbons LE, Teri L, Logsdon R, . Anxiety symptoms as predictors of nursing home placement in patients with Alzheimer’s disease. Journal of Clinical Geropsychology. 2002;8(4):335–342.
127 Bakker C, de Vugt ME, van Vliet D, . Predictors of the time to institutionalization in young-versus late-onset dementia: results from the Needs in Young Onset Dementia (NeedYD) study. J Am Med Dir Assoc. 2013;14(4):248–253.23123009
128 Bannister C, Ballard C, Lana M, Fairbairn A, Wilcock G. Placement of dementia sufferers in residential and nursing home care. Age Ageing. 1998;27(2):189–193.16296678
129 Coehlo DP. Residential placement of patients with dementia: Relationship to care recipient and caregiver variables. 1999.
130 Wang JJ, Mitchell P, Smith W, Cumming RG, Leeder SR. Incidence of nursing home placement in a defined community. Med J Aust. 2001;174(6):271–275.11297113
131 Lachs M, Bachman R, Williams CS, Kossack A, Bove C, O’Leary JR. Violent crime victimization increases the risk of nursing home placement in older adults. Gerontologist. 2006;46(5):583–589.17050749
132 Jette AM, Branch LG, Sleeper LA, Feldman H, Sullivan LM. High-risk profiles for nursing home admission. Gerontologist. 1992;32(5):634–640.1427275
133 Agüero-Torres H, von Strauss E, Viitanen M, Winblad B, Fratiglioni L. Institutionalization in the elderly: the role of chronic diseases and dementia. Cross-sectional and longitudinal data from a population-based study. J Clin Epidemiol. 2001;54(8):795–801.11470388
134 Shapiro E, Tate RB. Predictors of long term care facility use among the elderly. Canadian Journal on Aging/la Revue Canadienne Du Vieillissement. 1985;4(1):11–19.
135 Lachs MS, Williams CS, O’Brien S, Pillemer KA. Adult protective service use and nursing home placement. Gerontologist. 2002;42(6):734–739.12451154
136 Russell DW, Cutrona CE, de la Mora A, Wallace RB. Loneliness and nursing home admission among rural older adults. Psychology and Aging. 1997;12(4):574.9416627
137 Zuckerman IH, Langenberg P, Baumgarten M, . Inappropriate drug use and risk of transition to nursing homes among community-dwelling older adults. Med Care. 2006;44(8):722.16862033
138 Eska K, Graessel E, Donath C, Schwarzkopf L, Lauterberg J, Holle R. Predictors of institutionalization of dementia patients in mild and moderate stages: a 4-year prospective analysis. Dement Geriatr Cogn Dis Extra. 2013;3(1):426–445.24348504
139 Gilley DW, McCann JJ, Bienias JL, Evans DA. Caregiver psychological adjustment and institutionalization of persons with Alzheimer’s disease. Journal of Aging and Health. 2005;17(2):172–189.15750050
140 McCann JJ, Hebert LE, Li Y, . The effect of adult day care services on time to nursing home placement in older adults with Alzheimer’s disease. Gerontologist. 2005;45(6):754–763.16326657
141 Argimon JM, Limon E, Vila J, Cabezas C. Health-related quality-of-life of care-givers as a predictor of nursing-home placement of patients with dementia. J Alzheimer Disease Associated Disorders. 2005;19(1):41–44.
142 Bharucha AJ, Pandav R, Shen C, Dodge HH, Ganguli M. Predictors of nursing facility admission: a 12-year epidemiological study in the United States. J Am Geriatr Soc. 2004;52(3):434–439.14962161
143 Griffin J, Meis L, Carlyle M, . Effectiveness of family and caregiver interventions on patient outcomes among adults with cancer or memory-related disorders: a systematic review. 2013.
144 Andrew T, Moriarty J, Levin E, Webb S. Outcome of referral to social services departments for people with cognitive impairment. Int J Geriatr Psychiatry. 2000;15(5):406–414.10822239
145 Bond MJ, Clark MS. Predictors of the decision to yield care of a person with dementia. Australasian Journal on Ageing. 2002;21(2):86–91.
146 Gaugler JE, Kane RL, Kane RA, Clay T, Newcomer R. Caregiving and institutionalization of cognitively impaired older people: utilizing dynamic predictors of change. Gerontologist. 2003;43(2):219–229.12677079
147 Callahan CM, Boustani MA, Unverzagt FW, . Effectiveness of collaborative care for older adults with Alzheimer disease in primary care: a randomized controlled trial. JAMA. 2006;295(18):2148–2157.16684985
148 Chien WT, Lee IY. Randomized controlled trial of a dementia care programme for families of home-resided older people with dementia. J Adv Nurs. 2011;67(4):774–787.21198803
149 Chien WT, Lee YM. A disease management program for families of persons in Hong Kong with dementia. Psychiatr Serv. 2008;59(4):433–436.18378844
150 Chu P, Edwards J, Levin R, Thomson J. The use of clinical case management for early stage Alzheimer’patients and their families. Am J Alzheimers Dis Other Demen. 2000;15(5):284–290.
151 Eloniemi-Sulkava U, Notkola IL, Hentinen M, Kivela SL, Sivenius J, Sulkava R. Effects of supporting community-living demented patients and their caregivers: a randomized trial. J Am Geriatr Soc. 2001;49(10):1282–1287.11890485
152 Eloniemi-Sulkava U, Saarenheimo M, Laakkonen ML, . Family care as collaboration: effectiveness of a multicomponent support program for elderly couples with dementia. Randomized controlled intervention study. J Am Geriatr Soc. 2009;57(12):2200–2208.20121986
153 Jansen AP, van Hout HP, Nijpels G, . Effectiveness of case management among older adults with early symptoms of dementia and their primary informal caregivers: a randomized clinical trial. Int J Nurs Stud. 2011;48(8):933–943.21356537
154 Lam LC, Lee JS, Chung JC, Lau A, Woo J, Kwok TC. A randomized controlled trial to examine the effectiveness of case management model for community dwelling older persons with mild dementia in Hong Kong. Int J Geriatr Psychiatry. 2010;25(4):395–402.19606455
155 Newcomer R, Yordi C, DuNah R, Fox P, Wilkinson A. Effects of the Medicare Alzheimer’s Disease Demonstration on caregiver burden and depression. Health Serv Res. 1999;34(3):669–689.10445897
156 Brodaty H, Gresham M, Luscombe G. THE PRINCE HENRY HOSPITAL DEMENTIA CAREGIVERS’TRAINING PROGRAMME. J International journal of geriatric psychiatry. 1997;12(2):183–192.
157 Duru OK, Ettner SL, Vassar SD, Chodosh J, Vickrey BG. Cost evaluation of a coordinated care management intervention for dementia. Am J Manag Care. 2009;15(8):521–528.19670955
158 Fortinsky RH, Kulldorff M, Kleppinger A, Kenyon-Pesce L. Dementia care consultation for family caregivers: collaborative model linking an Alzheimer’s association chapter with primary care physicians. Aging Ment Health. 2009;13(2):162–170.19347683
159 Gaugler JE, Roth DL, Haley WE, Mittelman MS. Can counseling and support reduce burden and depressive symptoms in caregivers of people with Alzheimer’s disease during the transition to institutionalization? Results from the New York University caregiver intervention study. Journal of the American Geriatrics Society. 2008;56(3):421–428.18179495
160 Miller R, Newcomer R, Fox P. Effects of the Medicare Alzheimer’s Disease Demonstration on nursing home entry. Health Serv Res. 1999;34(3):691–714.10445898
161 Mittelman MS, Ferris SH, Shulman E, Steinberg G, Levin B. A family intervention to delay nursing home placement of patients with Alzheimer disease. A randomized controlled trial. JAMA. 1996;276(21):1725–1731.8940320
162 Mohide EA, Pringle DM, Streiner DL, Gilbert JR, Muir G, Tew M. A randomized trial of family caregiver support in the home management of dementia. J Am Geriatr Soc. 1990;38(4):446–454.2184186
163 Nobili A, Riva E, Tettamanti M, . The effect of a structured intervention on caregivers of patients with dementia and problem behaviors: a randomized controlled pilot study. Alzheimer Dis Assoc Disord. 2004;18(2):75–82.15249851
164 Teri L, Gibbons LE, McCurry SM, . Exercise plus behavioral management in patients with Alzheimer disease: a randomized controlled trial. JAMA. 2003;290(15):2015–2022.14559955
165 Vernooij-Dassen M. Dementia and Homecare: Determinants of the sense of Competence of Primary Caregivers and the effect of Professionally Guided Caregiver Support. J Lisse: Sweta Zeitlinger. 1993.
166 Wray LO, Shulan MD, Toseland RW, Freeman KE, Vasquez BE, Gao J. The effect of telephone support groups on costs of care for veterans with dementia. Gerontologist. 2010;50(5):623–631.20507926
167 Wright LK, Litaker M, Laraia MT, DeAndrade S. Continuum of care for Alzheimer’s disease: a nurse education and counseling program. Issues Ment Health Nurs. 2001;22(3):231–252.11885210
168 Challis D, von Abendorff R, Brown P, Chesterman J, Hughes J. Care management, dementia care and specialist mental health services: an evaluation. Int J Geriatr Psychiatry. 2002;17(4):315–325.11994884
169 Eggert GM, Zimmer JG, Hall WJ, Friedman B. Case management: a randomized controlled study comparing a neighborhood team and a centralized individual model. Health Serv Res. 1991;26(4):471–507.1917502
170 Mittelman MS, Brodaty H, Wallen AS, Burns A. A three-country randomized controlled trial of a psychosocial intervention for caregivers combined with pharmacological treatment for patients with Alzheimer disease: effects on caregiver depression. Am J Geriatr Psychiatry. 2008;16(11):893–904.18978250
171 Mittelman MS, Haley WE, Clay OJ, Roth DL. Improving caregiver well-being delays nursing home placement of patients with Alzheimer disease. Neurology. 2006;67(9):1592–1599.17101889
172 Bernabei R, Landi F, Gambassi G, . Randomised trial of impact of model of integrated care and case management for older people living in the community. BMJ. 1998;316(7141):1348–1351.9563983
173 Boult C, Reider L, Leff B, . The effect of guided care teams on the use of health services: results from a cluster-randomized controlled trial. Arch Intern Med. 2011;171(5):460–466.21403043
174 Lewin G, De San Miguel K, Knuiman M, . A randomised controlled trial of the Home Independence Program, an Australian restorative home-care programme for older adults. Health Soc Care Community. 2013;21(1):69–78.23009672
175 Belle SH, Burgio L, Burns R, . Enhancing the quality of life of dementia caregivers from different ethnic or racial groups: a randomized, controlled trial. Ann Intern Med. 2006;145(10):727–738.17116917
176 Gaugler JE, Reese M, Mittelman MS. Effects of the NYU caregiver intervention-adult child on residential care placement. Gerontologist. 2013;53(6):985–997.23339050
177 Burch S, Longbottom J, McKay M, Borland C, Prevost T. A randomized controlled trial of day hospital and day centre therapy. Clin Rehabil. 1999;13(2):105–112.10348390
178 Crotty M, Giles LC, Halbert J, Harding J, Miller M. Home versus day rehabilitation: a randomised controlled trial. Age Ageing. 2008;37(6):628–633.18723862
179 Eagle DJ, Guyatt GH, Patterson C, Turpie I, Sackett B, Singer J. Effectiveness of a geriatric day hospital. CMAJ. 1991;144(6):699–704.1998929
180 Gladman JR, Lincoln NB, Barer DH. A randomised controlled trial of domiciliary and hospital-based rehabilitation for stroke patients after discharge from hospital. J Neurol Neurosurg Psychiatry. 1993;56(9):960–966.8410035
181 Hedrick S, Branch L. THE ADULT DAY HEALTH-CARE EVALUATION STUDY. In: LIPPINCOTT-RAVEN PUBL 227 EAST WASHINGTON SQ, PHILADELPHIA, PA 19106; 1993
182 Hui E, Lum CM, Woo J, Or KH, Kay RL. Outcomes of elderly stroke patients. Day hospital versus conventional medical management. Stroke. 1995;26(9):1616–1619.7660408
183 Masud T, Coupland C, Drummond A, . Multifactorial day hospital intervention to reduce falls in high risk older people in primary care: a multi-centre randomised controlled trial [ISRCTN46584556]. Trials. 2006;7(1):5.16542012
184 Pitkälä K. The effectiveness of day hospital care on home care patients. J Am Geriatr Soc. 1998;46(9):1086–1090.9736100
185 Tucker MA, Davison JG, Ogle SJ. Day hospital rehabilitation--effectiveness and cost in the elderly: a randomised controlled trial. Br Med J (Clin Res Ed). 1984;289(6453):1209–1212.
186 Vetter N, Smith A, Sastry D, Tinker G. Day Hospital: pilot study report. Research Team for the Care of Elderly People; 1989.
187 Weissert W, Wan T, Livieratos B, Katz S. Effects and costs of day-care services for the chronically ill: a randomized experiment. Med Care. 1980;18(6):567–584.6772889
188 Woodford-Williams E, Mc KJ, Trotter IS, Watson D, Bushby C. The day hospital in the community care of the elderly. Gerontol Clin (Basel). 1962;4(3):241–256.14008212
189 Young JB, Forster A. The Bradford community stroke trial: results at six months. BMJ. 1992;304(6834):1085–1089.1586821
190 Lawton MP, Brody EM, Saperstein AR. A controlled study of respite service for caregivers of Alzheimer’s patients. Gerontologist. 1989;29(1):8–16.2753374
191 Conlin MM, Caranasos GJ, Davidson RA. Reduction of caregiver stress by respite care: a pilot study. South Med J. 1992;85(11):1096–1100.1439947
192 Zarit SH, Stephens MAP, Townsend A, Greene R. Stress reduction for family caregivers: Effects of adult day care use. J Gerontol B Psychol Sci Soc Sci. 1998;53(5):S267–S277.9750575
193 Kosloski K, Montgomery RJ, Youngbauer JG. Utilization of respite services: A comparison of users, seekers, and nonseekers. J Appl Gerontol. 2001;20(1):111–132.
194 Riordan J, Bennett A. An evaluation of an augmented domiciliary service to older people with dementia and their carers. Aging and Mental Health. 1998;2(2):137–143.
195 Carpenter G, Demopoulos G. Screening the elderly in the community: controlled trial of dependency surveillance using a questionnaire administered by volunteers. BMJ. 1990;300(6734):1253–1256.2354297
196 Hendriksen C, Lund E, Strømgård E. Consequences of assessment and intervention among elderly people: a three year randomised controlled trial. Br Med J. 1984;289(6457):1522–1524.6439298
197 Pathy MJ, Bayer A, Harding K, Dibble A. Randomised trial of case finding and surveillance of elderly people at home. The Lancet. 1992;340(8824):890–893.
198 Stuck AE, Aronow HU, Steiner A, . A trial of annual in-home comprehensive geriatric assessments for elderly people living in the community. N Engl J Med. 1995;333(18):1184–1189.7565974
199 van Rossum E, Frederiks CM, Philipsen H, Portengen K, Wiskerke J, Knipschild P. Effects of preventive home visits to elderly people. BMJ. 1993;307(6895):27–32.8343668
200 Byles JE, Tavener M, O’Connell RL, . Randomised controlled trial of health assessments for older Australian veterans and war widows. Med J Aust. 2004;181(4):186–190.15310251
201 Gunner-Svensson F, Ipsen J, Olsen J, Waldstrom B. Prevention of relocation of the aged in nursing homes. Scand J Prim Health Care. 1984;2(2):49–56.6544449
202 Hall N, De Beck P, Johnson D, Mackinnon K, Gutman G, Glick N. Randomized trial of a health promotion program for frail elders. Canadian Journal on Aging/La Revue Canadienne du vieillissement. 1992;11(1):72–91.
203 Stuck AE, Minder CE, Peter-Wüest I, . A randomized trial of in-home visits for disability prevention in community-dwelling older people at low and high risk for nursing home admission. Arch Intern Med. 2000;160(7):977–986.10761963
204 Thomas R, Worrall G, Elgar F, Knight J. Can they keep going on their own? A four-year randomized trial of functional assessments of community residents. Canadian Journal on Aging/La Revue canadienne du vieillissement. 2007;26(4):379–389.
205 Wajnberg A, Wang KH, Aniff M, Kunins HV. Hospitalizations and skilled nursing facility admissions before and after the implementation of a home-based primary care program. J Am Geriatr Soc. 2010;58(6):1144–1147.20487075
206 Close J, Ellis M, Hooper R, Glucksman E, Jackson S, Swift C. Prevention of falls in the elderly trial (PROFET): a randomised controlled trial. Lancet. 1999;353(9147):93–97.10023893
207 Conroy S, Kendrick D, Harwood R, . A multicentre randomised controlled trial of day hospital-based falls prevention programme for a screened population of community-dwelling older people at high risk of falls. Age Ageing. 2010;39(6):704–710.20823124
208 Ferrer A, Formiga F, Sanz H, de Vries OJ, Badia T, Pujol R. Multifactorial assessment and targeted intervention to reduce falls among the oldest-old: a randomized controlled trial. Clin Interv Aging. 2014;9:383.24596458
209 Hogan DB, MacDonald FA, Betts J, . A randomized controlled trial of a community-based consultation service to prevent falls. CMAJ. 2001;165(5):537–543.11563205
210 Imhof L, Naef R, Wallhagen MI, Schwarz J, Mahrer-Imhof R. Effects of an advanced practice nurse in-home health consultation program for community-dwelling persons aged 80 and older. J Am Geriatr Soc. 2012;60(12):2223–2231.23194103
211 Newbury JW, Marley JE, Beilby JJ. A randomised controlled trial of the outcome of health assessment of people aged 75 years and over. Med J Aust. 2001;175(2):104–107.11556409
212 Spice CL, Morotti W, George S, . The Winchester falls project: a randomised controlled trial of secondary prevention of falls in older people. Age Ageing. 2009;38(1):33–40.18829689
213 Kovacs E, Prokai L, Meszaros L, Gondos T. Adapted physical activity is beneficial on balance, functional mobility, quality of life and fall risk in community-dwelling older women: a randomized single-blinded controlled trial. Eur J Phys Rehabil Med. 2013;49(3):301–310.23486300
214 Trombetti A, Hars M, Herrmann FR, Kressig RW, Ferrari S, Rizzoli R. Effect of music-based multitask training on gait, balance, and fall risk in elderly people: a randomized controlled trial. Arch Intern Med. 2011;171(6):525–533.21098340
215 Pardessus V, Puisieux F, Di Pompeo C, Gaudefroy C, Thevenon A, Dewailly P. Benefits of home visits for falls and autonomy in the elderly: a randomized trial study. Am J Phys Med Rehabil. 2002;81(4):247–252.11953541
216 Sherwood S, Morris JN. The Pennsylvania domiciliary care experiment: I. Impact on quality of life. Am J Public Health. 1983;73(6):646–653.6405641
217 Challis D, Darton R, Johnson L, Stone M, Traske K. An evaluation of an alternative to long-stay hospital care for frail elderly patients: II. Costs and effectiveness. Age Ageing. 1991;20(4):245–254.1656718
218 Kane RA. The noblest experiment of them all: learning from the national channeling evaluation. J Health Services Research. 1988;23(1):189.
219 Medicaid. Balancing Long Term Services & Supports https://www.medicaid.gov/medicaid/ltss/balancing/index.html.
220 Medicaid. Money Follows the Person.https://www.medicaid.gov/medicaid/ltss/money-follows-the-person/index.html.
221 U.S. Department of Health and Human Services Assistant Secretary for Planning and Evaluation Office of Disability. Aging and Long-Term Care Policy. 2018;https://aspe.hhs.gov/system/files/pdf/259521/LTSSMedicaid.pdf.
222 Geriatrics and Gerontology Advisory Committee. Meeting Minutes. September 27–28, 2018;https://www.va.gov/ADVISORY/docs/Minutes-GGACSep2018.pdf.
223 Veterans Experience Office. Choose Home Initiative Line of Action 1 Report. June 2018.
224 Branch LG, Katz S, Kniepmann K, Papsidero JA. A prospective study of functional status among community elders. Am J Public Health. 1984;74(3):266–268.6696160
225 Hardy SE, Gill TM. Recovery from disability among community-dwelling older persons. JAMA. 2004;291(13):1596–1602.15069047
226 Wysocki A, Butler M, Kane RL, Kane RA, Shippee T, Sainfort F. Long-Term Services and Supports for Older Adults: A Review of Home and Community-Based Services Versus Institutional Care. J Aging Soc Policy. 2015;27(3):255–279.25942005
227 Wysocki A, Kane RL, Golberstein E, Dowd B, Lum T, Shippee T. The association between long-term care setting and potentially preventable hospitalizations among older dual eligibles. Health Serv Res. 2014;49(3):778–797.24628471
228 Konetzka RT. The hidden costs of rebalancing long-term care. Health Serv Res. 2014;49(3):771–777.24831192
229 Grabowski DC. The cost-effectiveness of noninstitutional long-term care services: review and synthesis of the most recent evidence. Med Care Res Rev. 2006;63(1):3–28.16686071
230 Guo J, Konetzka RT, Magett E, Dale W. Quantifying long-term care preferences. Med Decis Making. 2015;35(1):106–113.25297656
231 Collins LM, Murphy SA, Nair VN, Strecher VJ. A strategy for optimizing and evaluating behavioral interventions. Ann Behav Med. 2005;30(1):65–73.16097907
232 Hemming K, Haines TP, Chilton PJ, Girling AJ, Lilford RJ. The stepped wedge cluster randomised trial: rationale, design, analysis, and reporting. BMJ. 2015;350:h391.25662947
233 Curran GM, Bauer M, Mittman B, Pyne JM, Stetler C. Effectiveness-implementation hybrid designs: combining elements of clinical effectiveness and implementation research to enhance public health impact. Med Care. 2012;50(3):217–226.22310560
234 Damschroder LJ, Aron DC, Keith RE, Kirsh SR, Alexander JA, Lowery JC. Fostering implementation of health services research findings into practice: a consolidated framework for advancing implementation science. Implement Sci. 2009;4:50.19664226
235 Carpenter CR, Shelton E, Fowler S, . Risk factors and screening instruments to predict adverse outcomes for undifferentiated older emergency department patients: a systematic review and meta-analysis. Acad Emerg Med. 2015;22(1):1–21.25565487
236 Dramé M, Novella J-L, Jolly D, . Rapid cognitive decline, one-year institutional admission and one-year mortality: analysis of the ability to predict and inter-tool agreement of four validated clinical frailty indexes in the SAFEs cohort. The journal of nutrition, health and aging. 2011;15(8):699–705.
237 Drubbel I, de Wit NJ, Bleijenberg N, Eijkemans RJ, Schuurmans MJ, Numans ME. Prediction of adverse health outcomes in older people using a frailty index based on routine primary care data. Journals of Gerontology Series A: Biomedical Sciences Medical Sciences. 2012;68(3):301–308.
238 Institute JBIJATJB. Joanna Briggs Institute reviewers’ manual: 2014 edition. 2014.
239 Karunananthan S, Wolfson C, Bergman H, Béland F, Hogan DB. A multidisciplinary systematic literature review on frailty: overview of the methodology used by the Canadian Initiative on Frailty and Aging. BMC medical research methodology. 2009;9(1):68.19821972
240 Schulz R, Zdaniuk B, Belle SH, Czaja SJ, Arrighi HM, Zbrozek AS. Baseline differences and trajectories of change for deceased, placed, and community residing Alzheimer’s disease patients. Alzheimer Dis Assoc Disord. 2010;24(2):143.20505432
241 Smith GE, O’Brien PC, Ivnik RJ, Kokmen E, Tangalos EG. Prospective analysis of risk factors for nursing home placement of dementia patients. Neurology. 2001;57(8):1467–1473.11673591
242 Stern Y, Tang MX, Albert MS, . Predicting time to nursing home care and death in individuals with Alzheimer disease. JAMA. 1997;277(10):806–812.9052710
243 Stevens A, Owen J, Roth D, Clay O, Bartolucci A, Haley W. Predictors of time to nursing home placement in White and African American individuals with dementia. J Aging Health. 2004;16(3):375–397.15155068
244 Fisher L, Lieberman MA. A longitudinal study of predictors of nursing home placement for patients with dementia: the contribution of family characteristics. Gerontologist. 1999;39(6):677–686.10650677
245 Mausbach BT, Coon DW, Depp C, . Ethnicity and time to institutionalization of dementia patients: a comparison of Latina and Caucasian female family caregivers. J Am Geriatr Soc. 2004;52(7):1077–1084.15209644
246 McGilchrist CA, Brodaty H, Peters KE, Harris L. Survival analysis and prognosis for dementia patients. J Biopharm Stat. 1994;4(1):113–125.8019580
247 Andrén S, Elmståhl S. Effective psychosocial intervention for family caregivers lengthens time elapsed before nursing home placement of individuals with dementia: a five-year follow-up study. International Psychogeriatrics. 2008;20(6):1177–1192.18606052
248 Camden A, Livingston G, Cooper C. Reasons why family members become carers and the outcome for the person with dementia: results from the CARD study. Int Psychogeriatr. 2011;23(9):1442–1450.21729411
249 de Vugt ME, Stevens F, Aalten P, Lousberg R, Jaspers N, Verhey FR. A prospective study of the effects of behavioral symptoms on the institutionalization of patients with dementia. Int Psychogeriatr. 2005;17(4):577–589.16185379
250 Habermann S, Cooper C, Katona C, Livingston G. Predictors of entering 24-h care for people with Alzheimer’s disease: results from the LASER-AD study. Int J Geriatr Psychiatry. 2009;24(11):1291–1298.19340893
251 Joling KJ, van Marwijk HW, van der Horst HE, . Effectiveness of family meetings for family caregivers on delaying time to nursing home placement of dementia patients: a randomized trial. PLoS ONE. 2012;7(8):e42145.22876304
252 Luck T, Luppa M, Weber S, . Time until institutionalization in incident dementia cases–results of the Leipzig Longitudinal Study of the Aged (LEILA 75+). Neuroepidemiology. 2008;31(2):100–108.18635941
253 Luppa M, Riedel-Heller SG, Stein J, . Predictors of institutionalisation in incident dementia–results of the German Study on Ageing, Cognition and Dementia in Primary Care Patients (AgeCoDe study). Dementia and Geriatric Cognitive Disorders. 2012;33(4):282–288.22759566
254 Philp I, McKee K, Armstrong G, . Institutionalization risk amongst people with dementia supported by family carers in a Scottish city. Aging and Mental Health. 1997;1(4):339–345.
255 Soto ME, Andrieu S, Gillette-Guyonnet S, Cantet C, Nourhashemi F, Vellas B. Risk factors for functional decline and institutionalisation among community-dwelling older adults with mild to severe Alzheimer’s disease: one year of follow-up. Age Ageing. 2006;35(3):308–310.16533876
256 Brodaty H, McGilchrist C, Harris L, Peters KE. Time until institutionalization and death in patients with dementia. Role of caregiver training and risk factors. Arch Neurol. 1993;50(6):643–650.8503802
257 Russell LB, Valiyeva E, Roman SH, Pogach LM, Suh DC, Safford MM. Hospitalizations, nursing home admissions, and deaths attributable to diabetes. Diabetes Care. 2005;28(7):1611–1617.15983309
258 Valiyeva E, Russell LB, Miller JE, Safford MM. Lifestyle-related risk factors and risk of future nursing home admission. Arch Intern Med. 2006;166(9):985–990.16682571
259 Akamigbo AB, Wolinsky FD. Reported expectations for nursing home placement among older adults and their role as risk factors for nursing home admissions. Gerontologist. 2006;46(4):464–473.16921000
260 Banaszak-Holl J, Fendrick AM, Foster NL, . Predicting nursing home admission: estimates from a 7-year follow-up of a nationally representative sample of older Americans. Alzheimer Dis Assoc Disord. 2004;18(2):83–89.15249852
261 Holroyd-Leduc JM, Mehta KM, Covinsky KE. Urinary incontinence and its association with death, nursing home admission, and functional decline. J Am Geriatr Soc. 2004;52(5):712–718.15086650
262 Foley DJ, Ostfeld AM, Branch LG, Wallace RB, McGloin J, Cornoni-Huntley JC. The risk of nursing home admission in three communities. J Aging Health. 1992;4(2):155–173.10117872
263 Freedman VA. Family structure and the risk of nursing home admission. J Gerontol B Psychol Sci Soc Sci. 1996;51(2):S61–69.8785694
264 Kersting RC. Impact of social support, diversity, and poverty on nursing home utilization in a nationally representative sample of older Americans. Soc Work Health Care. 2001;33(2):67–87.11760116
265 Speare Jr A, Avery R, Lawton L. Disability, residential mobility, and changes in living arrangements. J Gerontol. 1991;46(3):S133–S142.2030283
266 Steinbach U. Social networks, institutionalization, and mortality among elderly people in the United States. J Gerontol. 1992;47(4):S183–S190.1624713
267 Wolinsky FD, Callahan CM, Fitzgerald JF, Johnson RJ. The risk of nursing home placement and subsequent death among older adults. J Gerontol. 1992;47(4):S173–S182.1624712
268 Wolinsky FD, Callahan CM, Fitzgerald JF, Johnson RJ. Changes in functional status and the risks of subsequent nursing home placement and death. J Gerontol. 1993;48(3):S94–101.8482831
269 Cohen MA, Tell EJ, Wallack SS. Client-related risk factors of nursing home entry among elderly adults. J Gerontol. 1986;41(6):785–792.3534067
270 Harris Y. Depression as a risk factor for nursing home admission among older individuals. J Am Med Dir Assoc. 2007;8(1):14–20.17210498
271 Branch LG. Relative risk rates of nonmedical predictors of institutional care among elderly persons. J Comprehensive Therapy. 1984;10(7):33–40.
272 Eaker ED, Vierkant RA, Mickel SF. Predictors of nursing home admission and/or death in incident Alzheimer’s disease and other dementia cases compared to controls: a population-based study. J Clin Epidemiol. 2002;55(5):462–468.12007549
273 Kelman HR, Thomas C. Transitions between community and nursing home residence in an urban elderly population. Journal of Community Health. 1990;15(2):105–122.2355109
274 Palmore E. Total chance of institutionalization among the aged. Gerontologist. 1976;16(6):504–507.828603
275 Temkin-Greener H, Meiners MR. Transitions in long-term care. Gerontologist. 1995;35(2):196–206.7750776
276 Vicente L, Wiley JA, Carrington RA. The risk of institutionalization before death. Gerontologist. 1979;19(4):361–367.551938
277 Fischer LR, Green CA, Goodman MJ, . Community-based care and risk of nursing home placement. Med Care. 2003;41(12):1407–1416.14668673
278 Mustard C, Finlayson M, Derksen S, Berthelot J-MJJohsr, policy. What determines the need for nursing home admission in a universally insured population? Journal of Health Services Research and Policy. 1999;4(4):197–203.10623034
279 Klein T. Determinants of institutionalization in old age. In: Long-term care: Economic issues and policy solutions. Springer; 1996:103–113.
280 von Bonsdorff M, Rantanen T, Laukkanen P, Suutama T, Heikkinen E. Mobility limitations and cognitive deficits as predictors of institutionalization among community-dwelling older people. Gerontology. 2006;52(6):359–365.16905887
281 McCallum J, Simons LA, Simons J, Friedlander Y. Patterns and predictors of nursing home placement over 14 years: Dubbo study of elderly Australians. Australas J Ageing. 2005;24(3):169–173.
282 Woo J, Ho S, Yu A, Lau J. An estimate of long-term care needs and identification of risk factors for institutionalization among Hong Kong Chinese aged 70 years and over. J Gerontol A Biol Sci Med Sci. 2000;55(2):64–69.
283 Hayden JA, van der Windt DA, Cartwright JL, Cote P, Bombardier C. Assessing bias in studies of prognostic factors. Ann Intern Med. 2013;158(4):280–286.23420236
284 Higgins JP, Altman DG, Gotzsche PC, . The Cochrane Collaboration’s tool for assessing risk of bias in randomised trials. BMJ. 2011;343:d5928.22008217
285 Jadad AR, Moore RA, Carroll D, . Assessing the quality of reports of randomized clinical trials: is blinding necessary? Controlled clinical trials. 1996;17(1):1–12.8721797
286 Downs SH, Black N. The feasibility of creating a checklist for the assessment of the methodological quality both of randomised and non-randomised studies of health care interventions. J Epidemiol Community Health. 1998;52(6):377–384.9764259
287 Harris RP, Helfand M, Woolf SH, . Current methods of the US Preventive Services Task Force: a review of the process. Am J Prev Med. 2001;20:(3 Suppl):21–35.
288 Downs SH, Black N. The feasibility of creating a checklist for the assessment of the methodological quality both of randomised and non-randomised studies of health care interventions. Journal of Epidemiology Community Health. 1998;52(6):377–384.9764259
289 Kmet LM, Cook LS, Lee RC. Standard quality assessment criteria for evaluating primary research papers from a variety of fields. 2004.
290 Hirsch C. Review: home visiting with multidimensional assessment and multiple visits is effective in low risk elderly people. Evidence-Based Medicine. 2002;7(5):148–148.
291 Sørensen K, Sivertsen J. Follow-up three years after intervention to relieve unmet medical and social needs of old people. Comprehensive gerontology Section B, Behavioural, social, and applied sciences. 1988;2(2):85–91.
292 Tinetti ME, Baker DI, McAvay G, . A multifactorial intervention to reduce the risk of falling among elderly people living in the community. New England Journal of Medicine. 1994;331(13):821–827.8078528
293 van Haastregt JC, Diederiks JP, van Rossum E, de Witte LP, Voorhoeve PM, Crebolder HF. Effects of a programme of multifactorial home visits on falls and mobility impairments in elderly people at risk: randomised controlled trial. BMJ. 2000;321(7267):994–998.11039967
294 Vetter NJ, Lewis PA, Ford D. Can health visitors prevent fractures in elderly people? BMJ. 1992;304(6831):888–890.1392755
295 Caplan GA, Williams AJ, Daly B, Abraham K. A randomized, controlled trial of comprehensive geriatric assessment and multidisciplinary intervention after discharge of elderly from the emergency department—the DEED II study. J Am Geriatr Soc. 2004;52(9):1417–1423.15341540
296 Fabacher D, Josephson K, Pietruszka F, Linderborn K, Morley JE, Rubenstein LZ. An in-home preventive assessment program for independent older adults: a randomized controlled trial. J Am Geriatr Soc. 1994;42(6):630–638.8201149
297 Holland R, Lenaghan E, Harvey I, . Does home based medication review keep older people out of hospital? The HOMER randomised controlled trial. BMJ. 2005;330(7486):293.15665005
298 Kono A, Kanaya Y, Fujita T, . Effects of a preventive home visit program in ambulatory frail older people: a randomized controlled trial. J Gerontol A Biol Sci Med Sci. 2012;67(3):302–309.22016361
299 Shapiro A, Taylor M. Effects of a community-based early intervention program on the subjective well-being, institutionalization, and mortality of low-income elders. Gerontologist. 2002;42(3):334–341.12040135
300 van Hout HP, Jansen AP, van Marwijk HW, Pronk M, Frijters DF, Nijpels G. Prevention of adverse health trajectories in a vulnerable elderly population through nurse home visits: a randomized controlled trial [ISRCTN05358495]. J Journals of Gerontology Series A: Biomedical Sciences Medical Sciences. 2010;65(7):734–742.
301 Kono A, Kai I, Sakato C, Harker JO, Rubenstein LZ. Effect of preventive home visits for ambulatory housebound elders in Japan: a pilot study. Aging Clin Exp Res. 2004;16(4):293–299.15575123
302 Yamada Y, Ikegami N. Preventive home visits for community-dwelling frail elderly people based on Minimum Data Set Home Care: Randomized controlled trial. Geriatrics and Gerontology International. 2003;3(4):236–242.
303 Bouman A, Van Rossum E, Ambergen T, Kempen G, Knipschild P. Effects of a Home Visiting Program for Older People with Poor Health Status: A Randomized, Clinical Trial in the Netherlands: (See editorial comments by Drs. Andreas Stuck and Robert Kane, pp 561–563). Journal of the American Geriatrics Society. 2008;56(3):397–404.18179482
304 Sommers LS, Marton KI, Barbaccia JC, Randolph J. Physician, nurse, and social worker collaboration in primary care for chronically ill seniors. Arch Intern Med. 2000;160(12):1825–1833.10871977
305 Dalby DM, Sellors JW, Fraser FD, Fraser C, van Ineveld C, Howard M. Effect of preventive home visits by a nurse on the outcomes of frail elderly people in the community: a randomized controlled trial. CMAJ. 2000;162(4):497–500.10701382
306 Lenaghan E, Holland R, Brooks A. Home-based medication review in a high risk elderly population in primary care—the POLYMED randomised controlled trial. Age Ageing. 2007;36(3):292–297.17387123
307 Counsell SR, Callahan CM, Clark DO, . Geriatric care management for low-income seniors: a randomized controlled trial. JAMA. 2007;298(22):2623–2633.18073358
308 Force UPST. US preventive services task force procedure manual. 2008.
309 Verhagen AP, de Vet HC, de Bie RA, . The Delphi list: a criteria list for quality assessment of randomized clinical trials for conducting systematic reviews developed by Delphi consensus. J Clin Epidemiol. 1998;51(12):1235–1241.10086815