# Acknowledgments

This topic was developed in response to a nomination by Dr. Thomas O’Toole, Senior Medical Advisor, for the purpose of informing the VA Secretary’s Choose Home Initiative. The scope was further developed with input from the topic nominators (ie, operational partners), the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors gratefully acknowledge the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend TEP participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Thomas O’Toole, MD
  Senior Medical Advisor
  Office of the Assistant Deputy Undersecretary for Health – Clinical Operations (10NC)
  Veterans Health Administration, Washington D.C.
- Lynda C. Davis, PhD, MPA
  Chief Veterans Experience Officer
  Veterans Health Administration, Washington D.C.
- Margaret Kabat, LCSW-C, CCM
  Director, National Caregiver Support Program
  Veterans Health Administration, Washington D.C.
- Dayna Cooper, MSN, RN
  Director, Home and Community Based Care
  Office of Geriatrics and Extended Care (10NC4)
  Veterans Health Administration, Washington D.C

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Courtney Harold Van Houtven, PhD
  Durham VA HSR&D Center of Innovation
  Duke University School of Medicine
  Durham, NC
- James Rudolph, MD
  Director, Providence VA HSR&D Center of Innovation
  Warren Alpert Medical School of Brown University
  Providence, RI
- Lori Gerhard
  Office of Consumer Access & Self Determination
  Administration for Community Living, HHS
  Washington D.C.
- Michele Spoont, PhD
  Minneapolis VA HSR&D Center of Innovation and National Center for PTSD
  University of Minnesota Medical School
  Minneapolis, MN
- David Grabowski, PhD
  Harvard Medical School
  Boston, MA

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.