# Discussion

## Summary of Key Findings

To inform the VA Secretary’s Choose Home Initiative, we conducted a review of reviews to examine a wide range of risk factors and interventions to delay or prevent long-term NHP. We found 67 eligible reviews addressing these questions mainly for older adults with impairments or at high risk of developing impairments. We did not find any eligible review or research studies for individuals with PTSD and/or TBI. Key findings include:

- Frailty status and higher frailty scores were associated with higher risk for long-term NHP
- Functional impairments, including difficulty with ADL/IADL, demonstrated the most consistent and substantial associations with higher risk for long-term NHP
- Caregiver distress and/or burden was associated with higher risk for long-term NHP
- Case management, caregiver support, and preventive home visit interventions demonstrated no overall benefit for delaying or reducing long-term NHP across studies, but there were a few studies in each category which showed delays
- For a variety of other interventions, such as physical activity, home-based primary care, and assistive technologies, very limited to no evidence were available for effects on long-term NHP

The lack of effectiveness in general for interventions like case management reflects the complexity of factors contributing to long-term NHP and the challenges of conducting and evaluating multicomponent programs to address these factors. Review authors highlighted multiple difficulties with summarizing effects for such complex interventions. This included lack of clarity on the exact components for various interventions, which made it difficult to understand the critical nature of any single component or the potential requirement for a specific combination of components. Moreover, review authors noted that different groups of participants with variable underlying risk for long-term NHP were enrolled in different studies. In addition to potentially different mechanisms of action (eg, due to heterogeneity of risk factors for long-term NHP), this variability led to difficulty with determining whether individual studies were adequately powered to detect true intervention effects. Also, because of the high degree of variability across many dimensions, reviews were limited in ability to examine intervention and participant characteristics through subgroup analyses. Overall, effects of complex interventions are particularly challenging to evaluate and synthesize due to differences in components and variation in context for the interventions (including characteristics of both participants and the healthcare or community setting).

Our results also suggest critical questions about the potential impact of interventions to delay or prevent long-term NHP. First, which participants should be selected for interventions, or alternatively, when in the course of aging or a chronic illness should someone be considered for more intensive services or programs? At earlier or less severe stages of a chronic condition, interventions have a better chance of preventing the development of impairments and disease progression. However, challenges for such a public health approach include that many participants (in this lower risk group) must engage with the intervention, in order to see any appreciable benefit, and impacts may not be evident for many years. In the current US healthcare environment, the entity or organization that makes an upfront investment in such early interventions is unlikely to see the potential savings in resources from decreased future utilization of services. In contrast, interventions that target participants with many (or more intensive) existing care needs may have very limited ability to alter trajectories of decline for those at later stages of disability who have higher risk for long-term NHP. Current interventions aimed at these higher risk groups have largely sought to enhance coordination of services and caregiver resources, often with the hope that such efforts will enable existing informal support networks to continue meeting needs for adults with impairments. But some individuals with substantial needs will lack any support network, and social support can change quickly and dramatically (eg, death of a spouse). Our results suggest that many existing interventions would not sufficiently meet the needs of adults with impairments who have no informal caregiver support.

As noted above, addressing long-term NHP in the US is made more difficult by the fragmentation and complexity of the financial and regulatory environment for healthcare and long-term care services. These larger environmental factors make early investment (to reap long-term benefits) not financially feasible for many healthcare entities and community organizations. These factors also shape local availability (or lack thereof) to care and services, and thus limit the potential impact of individual interventions, such as case management, which must work with existing resources. Even limited demonstration projects of new financial benefits or incentives^218^ must operate within existing local barriers to care and services, including availability and quality of service providers. While a change in state or national policy may incentivize improved access and/or higher quality of HCBS (eg, current Medicaid rebalancing initiatives^219,220^), it may take many years to truly change the landscape of local resources.

## Implications for Policy

As an integrated national healthcare system that provides and/or funds services across the whole continuum of healthcare and community settings (including outpatient and inpatient services, HCBS and long-term nursing home care), VA may be better situated to ensure integration of services across settings to meet the entire range of needs for eligible Veterans with impairments. However, although VA provides many services through its own facilities and staff, VA also purchases substantial amounts of care provided by non-VA community agencies and organizations. This is especially true for long-term care services, where the vast majority of Veterans receiving VA-paid HCBS and nursing home care are served by non-VA providers.^1^ Thus, although VA has greater flexibility in provision and funding of services across settings, and greater ability to invest in early interventions, VA is also limited in delivery of care and services by the same local barriers to access and quality that apply to the general population of US adults with impairments. While VA spends a substantial proportion of its budget on long-term care services for eligible Veterans, this amounts to less than 10% of the annual Medicaid budget for long-term care services for elderly enrollees.^221^ Therefore, it seems unlikely that VA can change the landscape of local resources (and availability of new models of care), unless it strategically partners with organizations that determine the majority of financial incentives (and regulations) for long-term care service providers in the US.

Additionally, and likely in part due to variation in local resources, VA facilities differ in the number and types of long-term care programs and services that are provided and/or funded.^222^ Understanding what is available at a particular facility, and coordinating services across multiple programs within the same facility, remain key challenges for Veterans, their caregivers, and VA clinical staff.^223^ While there are a range of risk factors which may contribute to long-term NHP, no single factor, or small set of factors, reliably indicate which individuals will need long-term NHP. Moreover, most factors, including the degree of functional impairment, are dynamic over time.^224,225^ Thus, the salience of any particular program or service will also vary over time for individual Veterans at risk for long-term NHP. Therefore, in VA (as in non-VA settings), case management for adults with impairments may offer substantial benefits, despite the lack of effectiveness in general, as suggested by our results.

To impact long-term NHP, it is likely that case management (and other similar interventions that focus on caregiver support) should have relatively high-frequency longitudinal contacts with participants, be initiated early in the course of chronic conditions (eg, dementia), and extend for at least several years. Current VA programs likely do not provide comparable levels of support and care coordination over years, and implementing such high-intensity interventions may require substantial resources. As others have noted, there are also opportunities for VA to streamline its programs, and focus on consistently implementing a core set of evidence-based interventions across all facilities.^223^ This may improve the ability of Veterans, their caregivers, and VA staff to identify and engage in appropriate care, potentially without high-intensity case management. While more consistent assessment of impairments and social resources, including caregiver support, may help clinicians and the healthcare system predict which Veterans are at higher risk for long-term NHP, we think it unlikely that improved assessment will be sufficient to improve outcomes. Thus, we recommend implementation of robust, longitudinal, and coordinated services to address needs that are identified through better assessment.

Finally, to better serve Veterans with impairments, VA should be at the forefront of advancing our understanding of the value of HCBS versus institutional nursing home care. Past work has highlighted that we lack high-quality evidence on whether (and which) outcomes are improved with HCBS.^226^ Some have questioned whether the national push to shift funding to HCBS (and away from nursing homes) is wise, or if this will lead to worse outcomes for those with substantial needs,^227^ especially if numeric goals (eg, proportion of spending on HCBS) do not adequately account for the specific mix of needs for different populations.^228^ Our results support concerns that increased utilization of HCBS may not lead to appreciable changes in long-term NHP, and point to the importance of understanding the impact of HCBS on other outcomes. We agree with others who have encouraged policymakers to instead consider evaluating existing programs (and future interventions) in terms of cost-effectiveness due to improved patient and family-centered outcomes,^226,229^ and not solely in terms of avoiding costs of long-term NHP. The VA should implement rigorous evaluations of patient and family-centered outcomes for VA-provided and -funded services, to help establish the value and cost-effectiveness for different types of long-term care services.

Therefore, we suggest the following:

- Organize and streamline VA programs and services according to their key goals, which may include delaying long-term NHP or other important outcomes, such as caregiver support and wellbeing
- Compare VA programs that aim to prevent or delay long-term NHP with models of high-intensity interventions (eg, case management, caregiver support, and/or home visits) that have some evidence for effects on long-term NHP, and consider that lower-intensity programs may have low likelihood of changing long-term NHP
- Combine implementation of improved assessment for physical and cognitive impairments and social resources with programs to provide dedicated, longitudinal care coordination over years, in order to impact long-term NHP
- Evaluate programs (including alternative residential settings that provide a high level of care) for cost-effectiveness from improved patient and family-centered outcomes, rather than cost-savings (from avoidance of long-term NHP)
- Leverage past VA experience with implementation of complex programs that have addressed both healthcare and social needs for vulnerable Veterans, and develop new models of support for Veterans with substantial impairments

## Evidence Gaps & Future Research Needs

We found no review or studies that addressed risk factors or interventions to delay long-term NHP for individuals with PTSD and/or TBI. Perhaps this is because few individuals are at substantial risk of long-term NHP, although many require family support for mental health symptoms and mild cognitive impairment. However, questions regarding risk for long-term NHP should be examined in future studies.

Eligible reviews also found little evidence examining systems or environmental factors, such as local availability of HCBS, or appropriate and affordable housing. In part, this may be due to the selection criteria of eligible reviews examining risk factors, which often required longitudinal follow-up and excluded cross-sectional studies. As noted above, systems and environmental factors may be very important and limit the ability of individual interventions to address long-term NHP. Additionally, reviews did not identify evidence regarding certain personal and social factors, such as attitudes and preferences for setting of care. Some adults with impairments (and their caregivers) may have more positive attitudes toward institutional care and some preferences may change over time.^11,230^

As noted above, eligible reviews on interventions to prevent or delay long-term NHP reported difficulties with evaluation of complex interventions that often differed along multiple dimensions, including in type and number of components, settings, and frequency and modality of participant contacts. Combined with heterogeneity in participant characteristics and settings for studies, this intervention complexity and variability created substantial challenges in understanding effects on long-term NHP. As complex interventions may be the most plausible way to enhance healthcare delivery and improve outcomes for various groups with complex needs, it is imperative that we consider methodologies to improve design and evaluation of such interventions. For example, the multiphase optimization strategy (MOST) can be employed to guide selection of intervention components that may work better for certain groups or in certain settings.^231^ Frameworks also exist for pragmatic trials and explicit consideration of implementation outcomes, along with effects on participant health and functioning (eg, stepped wedge and hybrid designs).^232,233^ One important benefit of applying an implementation science framework is the clarification between the “core” set of important components and an “adaptable periphery” of elements that can be adjusted to accommodate the local context for implementation^234^; this acknowledgment is key for considering intervention fidelity, interpreting effectiveness results, and enabling future implementation.

Therefore, we recommend the following for future research:

- Longitudinal observational studies examining whether individuals with PTSD and/or TBI are at substantial risk of long-term NHP
- Longitudinal studies on effect of factors such as attitudes and preferences for setting of care, and systems and environmental factors, including local availability of HCBS, on long-term NHP
- Randomized evaluations of complex interventions that compare models of care which differ in only 1–2 key components or characteristics (eg, similar types of services at home vs in clinic)
- Randomized evaluations of interventions with longer follow-up (likely > 2 years) and larger sample size, particularly if targeting individuals at lower overall risk of long-term NHP
- Consider using strategies to optimize selection of intervention components and evaluation designs that explicitly consider implementation outcomes in future studies of complex interventions to address long-term NHP

## Limitations

To address the priorities of our VA partners, this work focused on long-term NHP, and reviews that did not address long-term NHP were excluded. Although we also abstracted results for other outcomes (eg, mortality and hospitalizations for adults with impairments), we only examined prioritized reviews that evaluated long-term NHP. We excluded reviews that only addressed caregiver outcomes. Therefore, our findings do not indicate that interventions are not effective for other important outcomes for adults with impairments or their caregivers. We prioritized highest quality and more recent reviews to provide associations and effects for specific risk factors and interventions. We relied on review authors’ descriptions of interventions, quality ratings for included studies, and determination of overall strength of evidence. We examined included primary studies from only prioritized reviews, and our focus was primarily to provide an indication of the size of the underlying evidence base (ie, by counting the number of unique studies addressing different interventions and confirming ascertainment of long-term NHP in these studies). Most eligible reviews did not specify how they determined whether included studies addressed long-term NHP. In our examination of primary studies included in prioritized reviews, we found that most studies used participant or family reports of long-term NHP and few confirmed long-term NHP with additional data sources, such as state or federal administrative data on utilization of long-term care services. Examination of the primary studies also showed that few were conducted in the VA (a notable exception being research on HBPC, although these studies did not examine long-term NHP); however, evidence for the general population may be applicable to Veterans, given the likelihood of some shared risk factors that contribute to long-term NHP, as well as VA’s use of non-VA service providers for many Veterans with impairments. It may be that interventions in countries other than the US may be less relevant for Veterans and the VA, but we elected to include this evidence, as it may help inform future policy changes. Despite these limitations, our review provides important information about a wide range of risk factors and interventions to delay long-term NHP.

## Conclusion

Existing evidence on a wide range of risk factors and interventions for older adults demonstrated the complexity of contributors to long-term NHP and the difficulty of preventing or delaying this outcome. There was a lack of evidence evaluating certain risk factors, especially at the level of systems and environment. Very limited evidence suggested that high-intensity models of case management, caregiver support, and home visits may delay long-term NHP. Although there are a variety of VA programs and services that seek to help Veterans with impairments, many likely do not involve similar levels of participant contact and dedicated coordination of care and services over years, compared with those interventions that were able to change long-term NHP. Policymakers should consider evaluating cost-effectiveness of current and future VA programs in terms of improved patient and family-centered outcomes, and not solely as seeking to avoid costs of long-term NHP.